# APPENDIX A SEARCH STRATEGY

## OVID MEDLINE AND EMBASE

1 | exp Stress Disorders, Post-Traumatic/cl, di, dg, rh, th [Classification, Diagnosis, Diagnostic Imaging, Rehabilitation, Therapy]
2 | exp combat disorder/ or (post* stress dis* or ptsd or combat disord*).kw,tw.
3 | exp Depression/cl, di, dg, rh, th [Classification, Diagnosis, Diagnostic Imaging, Rehabilitation, Therapy]
4 | exp Depressive Disorder/cl, di, dg, rh, th [Classification, Diagnosis, Diagnostic Imaging, Rehabilitation, Therapy]
5 | (depress* or dysthymi* or MDD or major-depress* dis* or TRD or TRS).tw,kw.
6 | Substance-Related Disorders/cl, di, dg, rh, th [Classification, Diagnosis, Diagnostic Imaging, Rehabilitation, Therapy]
7 | ((problem adj2 (alcohol or drink$ or drug$ or substance)) or (substance adj2 abuse) or substance adj2disorder or ((alcohol or drug or tobacco) adj2 (abuse or addiction or disorder))).mp.
8 | ((Subst* adj2 disorder*) or SUD).kw,tw.
9 | Anxiety/cl, di, dg, rh, th [Classification, Diagnosis, Diagnostic Imaging, Rehabilitation, Therapy]
10 | Anxiety Disorders/cl, di, dg, rh, th [Classification, Diagnosis, Diagnostic Imaging, Rehabilitation, Therapy]
11 | (anxiety or anxio* or phobi* or agoraphobi* or panic or neurosis or neuroses or neurotic or psychoneuro* or post-trauma* or stress disorder or obsessi* or compul* or OCD or obsessive compulsive disorde* or generalized anxiety disorder or GAD).tw,kw.
12 | Bipolar Disorder/cl, di, dg, rh, th [Classification, Diagnosis, Diagnostic Imaging, Rehabilitation, Therapy]
13 | ((bipolar adj2 dis*) or manic-depress*).kw,tw.
14 | Brain Injuries, Traumatic/cl, di, dg, rh, th [Classification, Diagnosis, Diagnostic Imaging, Rehabilitation, Therapy]
15 | (brain injur* or TBI or concuss* or head injur* or post-concuss*).tw,kw.
16 | or/1-15
17 | exp Functional Neuroimaging/ or functional neuroimaging.tw,kw.
18 | exp Magnetic Resonance Imaging/ or (Magnetic Resonance Imaging or MRI or fMRI).tw,kw.
19 | (diffusion tensor imag* or DTI).kw,tw.
20 | (voxel-based morphometry or VBM).tw,kw.
21 | (tractograph* or tractometr*).kw,tw.
22 | (arterial spin label* or ASL).tw,kw.
23 | exp tomography, emission-computed/ or ((positron* adj4 tomograph*) or emission-computed or single photon or SPECT).tw,kw.
24 | exp magnetic resonance spectroscopy/ or (magnetic resonance spectroscopy or MR spectroscopy or MRS).tw,kw.
25 | exp electroencephalography/ or (electroencephalograph* or EEG).tw,kw.
26 | exp magnetoencephalography/ or (magnetoencephalograph* or MEG).tw,kw.
27 | exp Evoked Potentials/ or (evoked response* or evoked potential*).tw,kw.
28 | or/17-27
29 | 16 and 28
30 | ((animal or animals or canine* or cat or cats or dog or dogs or feline or goat or hamster* or horse or lamb or lambs or mice or monkey or monkeys or mouse or murine or pig or pigs or piglet* or porcine or primate* or rabbit* or rats or rat or rodent* or sheep* or veterinar*) not (human* or patient*)).ti,kf,jw.
31 | (Animals/ or Models, Animal/ or Disease Models, Animal/) not Humans/
32 | 30 or 31
33 | 29 not 32
34 | limit 33 to (english language and yr="2010 - 2022")
35 | limit 34 to (addresses or autobiography or bibliography or biography or case reports or comment or dictionary or directory or editorial or interactive tutorial or interview or legal cases or legislation or news or newspaper article or patient education handout or periodical index or personal narratives or portraits or video-audio media or webcasts)
36 | 34 not 35
37 | limit 36 to (juvenile or infan$ or child$)
38 | 36 not 37