# REFERENCES

1 American Healthcare Documentation Professionals Group. Medical Scribe - The Job Description. https://ahdpg.com/medical-scribe-the-job-description/. Accessed 07/01/2020.
2 Oregon Health and Science University. Medical Scribes History. https://www.ohsu.edu/medical-scribes/history-and-results. Accessed 07/01/2020.
3 Heaton HA, Castaneda-Guarderas A, Trotter ER, Bellolio MF, Erwin PJ. Impact of scribes: A systematic review and meta-analysis. Academic Emergency Medicine. 2016;23:S62.
4 Cabilan CJ, Eley RM. Review article: Potential of medical scribes to allay the burden of documentation and enhance efficiency in Australian emergency departments. Emerg Med Australas. 2015;27(6):507–511.26268590
5 Shultz CG, Holmstrom HL. The use of medical scribes in health care settings: A systematic review and future directions. Journal of the American Board of Family Medicine. 2015;28(3):371–381.25957370
6 Holroyd-Leduc JM, Lorenzetti D, Straus SE, Sykes L, Quan H. The impact of the electronic medical record on structure, process, and outcomes within primary care: a systematic review of the evidence. Journal of the American Medical Informatics Association. 2011;18(6):732–737.21659445
7 King J, Patel V, Jamoom EW, Furukawa MF. Clinical benefits of electronic health record use: national findings. Health services research. 2014;49(1pt2):392–404.24359580
8 Boonstra A, Broekhuis M. Barriers to the acceptance of electronic medical records by physicians from systematic review to taxonomy and interventions. BMC Health Serv Res. 2010;10:231.20691097
9 McLean SA, Feldman JA. The impact of changes in HCFA documentation requirements on academic emergency medicine: results of a physician survey. Acad Emerg Med. 2001;8(9):880–885.11535480
10 Finkelstein J, Lifton J, Capone C. Redesigning physician compensation and improving ED performance. Healthc Financ Manage. 2011;65(6):114–117.
11 Brady K, Shariff A. Virtual medical scribes: making electronic medical records work for you. J Med Pract Manage. 2013;29(2):133–136.24228379
12 U.S. Congress. VA MISSION Act of 2018. https://www.congress.gov/115/bills/s2372/BILLS-115s2372enr.pdf.
13 Sterne JA, Hernan MA, Reeves BC, . ROBINS-I: a tool for assessing risk of bias in non-randomised studies of interventions. BMJ. 2016;355:i4919.27733354
14 Higgins JP, Altman DG, Gotzsche PC, . The Cochrane Collaboration’s tool for assessing risk of bias in randomised trials. BMJ. 2011;343:d5928.22008217
15 Mishra P, Kiang JC, Grant RW. Association of Medical Scribes in Primary Care With Physician Workflow and Patient Experience. JAMA Intern Med. 2018;178(11):1467–1472.30242380
16 Shultz CG, Holmstrom HL. The use of medical scribes in health care settings: a systematic review and future directions. The Journal of the American Board of Family Medicine. 2015;28(3):371–381.25957370
17 George A, Gellert M. The Rise of the Medical Scribe Industry Implications for the Advancement of Electronic Health Records. 2014.
18 American College of Medical Scribe Specialists. Becoming Licensed – Certified Medical Scribe Specialist. https://acmss.org/become-cmss-licensed/. Accessed 7/01/2020.
19 American Healthcare Documentation Professionals Group. The MSCE. https://ahdpg.com/scribe-certification/. Accessed 07/01/2020.
20 Centers for Medicare and Medicaid and Services. Recommended Core Measures. https://www.cms.gov/Regulations-and-Guidance/Legislation/EHRIncentivePrograms/Recommended_Core_Set. Accessed 07/01/2020.
21 Glassdoor. Medical Scribe Salary. https://www.glassdoor.com/Salaries/minneapolis-medical-scribe-salary-SRCH_IL.0,11_IM567_KO12,26.htm (https://www.glassdoor.com/Salaries/minneapolis-medical-scribe-salary-SRCH_IL.0.11_IM567_KO12.26.htm) Accessed 06/22/2020.
22 ScribeAmerica. FAQs. https://www.scribeamerica.com/faq/. Accessed 06/22/2020.
23 Medical Scribes Training Institute. Medical Scribe Program Implementation: 8 Key Decisions When Hiring Scribes. https://medicalscribes.org/medical-scribe-program-implementation-8-key-decisions-when-hiring-scribes/ 06/22/2020.
24 Centers for Medicare and Medicaid and Services. Finalized Policy, Payment, and Quality Provisions Changes to the Medicare Physician Fee Schedule for Calendar Year 2020. https://www.cms.gov/newsroom/fact-sheets/finalized-policy-payment-and-quality-provisions-changes-medicare-physician-fee-schedule-calendar. Accessed 07/01/2020.
25 Murad MH, Mustafa RA, Schunemann HJ, Sultan S, Santesso N. Rating the certainty in evidence in the absence of a single estimate of effect. Evid Based Med. 2017;22(3):85–87.28320705
26 Malmivaara A. Methodological considerations of the GRADE method. In: Taylor & Francis; 2015
27 Balshem H, Helfand M, Schunemann HJ, . GRADE guidelines: 3. Rating the quality of evidence. J Clin Epidemiol. 2011;64(4):401–406.21208779
28 Bank AJ, Obetz C, Konrardy A, . Impact of scribes on patient interaction, productivity, and revenue in a cardiology clinic: a prospective study. Clinicoecon Outcomes Res. 2013;5(1):399–406.23966799
29 Bank AJ, Gage RM. Annual impact of scribes on physician productivity and revenue in a cardiology clinic. Clinicoecon Outcomes Res. 2015;7:489–495.26457055
30 Walker K, Ben-Meir M, O’Mullane P, Phillips D, Staples M. Scribes in an Australian private emergency department: A description of physician productivity. Emerg Med Australas. 2014;26(6):543–548.25330990
31 Walker KJ, Ben-Meir M, Phillips D, Staples M. Medical scribes in emergency medicine produce financially significant productivity gains for some, but not all emergency physicians. EMA - Emergency Medicine Australasia. 2016;28(3):262–267.26954293
32 Walker KJ, Dunlop W, Liew D, . An economic evaluation of the costs of training a medical scribe to work in Emergency Medicine. Emerg Med J. 2016;33(12):865–869.27352788
33 Walker KJ, Wang A, Dunlop W, Rodda H, Ben-Meir M, Staples M. The 9-Item Physician Documentation Quality Instrument (PDQI-9) score is not useful in evaluating EMR (scribe) note quality in Emergency Medicine. Applied clinical informatics. 2017;8(3):981–993.28956888
34 Dunlop W, Hegarty L, Staples M, Levinson M, Ben-Meir M, Walker K. Medical scribes have no impact on the patient experience of an emergency department. EMA - Emergency Medicine Australasia. 2018;30(1):61–66.28589691
35 Walker K, Ben-Meir M, Dunlop W, . Impact of scribes on emergency medicine doctors’ productivity and patient throughput: multicentre randomised trial. BMJ. 2019;364:l121.30700408
36 Heaton HA, Nestler DM, Jones DD, . Impact of scribes on patient throughput in adult and pediatric academic EDs. Am J Emerg Med. 2016;34(10):1982–1985.27450391
37 Heaton HA, Nestler DM, Lohse CM, Sadosty AT. Impact of scribes on emergency department patient throughput one year after implementation. Am J Emerg Med. 2017;35(2):311–314.27856140
38 Heaton HA, Nestler DM, Jones DD, . Impact of Scribes on Billed Relative Value Units in an Academic Emergency Department. J Emerg Med. 2017;52(3):370–376.27988262
39 Heaton HA, Wang R, Farrell KJ, . Time Motion Analysis: Impact of Scribes on Provider Time Management. J Emerg Med. 2018;55(1):135–140.29807680
40 Heaton HA, Nestler DM, Barry WJ, . A Time-Driven Activity-Based Costing Analysis of Emergency Department Scribes. Mayo Clin Proc Innov Qual Outcomes. 2019;3(1):30–34.30899906
41 Heaton HA, Schwartz EJ, Gifford WJ, . Impact of scribes on throughput metrics and billing during an electronic medical record transition. Am J Emerg Med. 2019;(no pagination).
42 Allen B, Banapoor B, Weeks EC, Payton T. An assessment of emergency department throughput and provider satisfaction after the implementation of a scribe program. Advances in Emergency Medicine. 2014;2014.
43 Arya R, Salovich DM, Ohman-Strickland P, Merlin MA. Impact of scribes on performance indicators in the emergency department. Acad Emerg Med. 2010;17(5):490–494.20536801
44 Bastani A, Shaqiri B, Palomba K, Bananno D, Anderson W. An ED scribe program is able to improve throughput time and patient satisfaction. American Journal of Emergency Medicine. 2014;32(5):399–402.
45 Friedson AI. Medical Scribes as an Input in Health-Care Production: Evidence from a Randomized Experiment. American Journal of Health Economics. 2018;4(4):479–503.
46 Graves PS, Graves SR, Minhas T, Lewinson RE, Vallerand IA, Lewinson RT. Effects of medical scribes on physician productivity in a Canadian emergency department: a pilot study. CMAJ Open. 2018;6(3):E360–E364.
47 Hess JJ, Wallenstein J, Ackerman JD, . Scribe Impacts on Provider Experience, Operations, and Teaching in an Academic Emergency Medicine Practice. West J Emerg Med. 2015;16(5):602–610.26587079
48 Ou E, Mulcare M, Clark S, Sharma R. Implementation of Scribes in an Academic Emergency Department: The Resident Perspective. J Grad Med Educ. 2017;9(4):518–522.28824769
49 Shuaib W, Hilmi J, Caballero J, . Impact of a scribe program on patient throughput, physician productivity, and patient satisfaction in a community-based emergency department. Health Informatics J. 2017:1460458217692930.29239230
50 Stetson PD, Morrison FP, Bakken S, Johnson SB, eNote Research T. Preliminary development of the physician documentation quality instrument. J Am Med Inform Assoc. 2008;15(4):534–541.18436914
51 ScribeKick. Virtual Scribe. https://www.scribekick.com/virtual-scribe/. Accessed 07/01/2020.