# ACKNOWLEDGMENTS

This topic was developed in response to a nomination by Storm Morgan, Program Manager, Office of Nursing Services, on behalf of the Section 507 Committee, for the purpose of informing the Section 507 Committee on the effect of medical scribes in cardiology, orthopedic, or emergency department clinics. This report will be used in conjunction with an evaluation to a pilot on the effects of medical scribes which was mandated by Section 507 of the MISSION Act. The scope was further developed with input from the topic nominators (ie, Operational Partners), the ESP Coordinating Center, the review team, and the technical expert panel (TEP).

In designing the study questions and methodology at the outset of this report, the ESP consulted several technical and content experts. Broad expertise and perspectives were sought. Divergent and conflicting opinions are common and perceived as healthy scientific discourse that results in a thoughtful, relevant systematic review. Therefore, in the end, study questions, design, methodologic approaches, and/or conclusions do not necessarily represent the views of individual technical and content experts.

The authors gratefully acknowledge the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who have requested the report to inform decision-making. They recommend Technical Expert Panel (TEP) participants; assure VA relevance; help develop and approve final project scope and timeframe for completion; provide feedback on draft report; and provide consultation on strategies for dissemination of the report to field and relevant groups.

- Storm Morgan, MSN, MBA, RN
  Program Manager
  Office of Nursing Services

## Technical Expert Panel (TEP)

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Steve Pizer, PhD
  Chief Economist, Partnered Evidence-Based Policy Resource Center
  Director of Health Law, Policy and Management, Boston University
  Boston, MA
- Max Napolitano, MPAS
  Medical Scribe and Medical Scribe Trainer (former), North Memorial Medical Center
  Minneapolis, MN
- Lauren Klein, MD, MS
  ED and Scribe Program Director, Hennepin County Medical Center
  Minneapolis, MN

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence. Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center and the ESP Center work to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.