# SUMMARY AND DISCUSSION

Findings from our systematic review on the effects of medical scribes in orthopedic, cardiology, and emergency departments are limited by the quantity, quality, completeness, and applicability of information. Available information is based on studies mostly rated as having serious risk of bias and of limited applicability to widespread implementation. There are no data in VA health care settings or among Veterans. Much of the information from emergency departments is from 2 single-site centers (one from Australia and another from the US). Thus, findings across multiple reports from these groups are likely to be highly correlated even though they are not considered duplicate outcomes reporting. Studies typically recruited interested clinician participants and began data collection following scribe and clinician training run-in periods. Studies did not report all outcomes of interest and rarely provided adequate information on resources required to hire, train, maintain, and supervise scribes.

No data were identified on medical scribes in orthopedic clinics. In cardiology clinics the efficiency and financial productivity of scribe programs is uncertain, with findings based on a single, serious risk of bias study from a cardiology group in Minneapolis, MN that evaluated medical scribes provided by a vendor. No data are available on the effect of medical scribes on patient and provider satisfaction in cardiology clinics.

Most of our findings are from studies conducted in emergency departments, much of them limited to 2 groups publishing multiple results of various measures of scribe related outcomes. In emergency departments, medical scribes may improve efficiency (low certainty of evidence [COE]) and financial productivity (low COE). The magnitude of effect on efficiency is likely small to moderate. Efficiency varies based on the setting, outcomes assessed, and methods for evaluating financial productivity. The effect on costs is difficult to ascertain as complete cost reporting was not provided. Resources to identify, hire, train, staff, maintain, and monitor a scribe program are expected to be substantial, rarely reported in the literature, and not readily available through online searches. Thus, net financial impact is not known and likely varies by key assumptions and methods for scribe program development, implementation, and maintenance. All the studies that reported on financial productivity reported estimations based on a typical scribe salary and average billings, and none of the identified studies were true economic evaluations incorporating all costs attributed to the scribe intervention, including administrative or supervisory cost; the cost of identifying, hiring, training, supervising, maintaining, or replacing scribes; documentation verification costs; or costs related to contracting through outside vendors. Medical scribes may make little to no difference in door-to-room or door-to-provider time, number of patients who left without being seen, and patient or clinician satisfaction, though results were mixed. There are no direct comparative data on quality of documentation, medical errors, or scribe training (eg, time to train, turnover), and no data comparing these outcomes in contracted (ie, vendor supplied) scribes versus scribes trained in-house or using virtual scribes.

We identified only 1 study that provided a detailed analysis of the implementation of a scribe training program, which was implemented in Australia. Few US studies provided any details about scribe training, and no studies described the time it takes to orient a contracted scribe to the health care facility in which they are working.

The data identified from the emergency departments are not necessarily generalizable to other clinics, as these departments function differently, have variation in measured metrics (ie, panel size vs number of patients seen per day) and have a different financial model. Outcomes of interest to emergency departments are not necessarily the same as other specialty clinics. For example, an emergency department may be able to alter staffing schedules if 1 doctor can see more patients in a shift, where the only way to alter the number of patients seen in a shift in the cardiology clinic is to alter the clinicians schedule. The single cardiology study we identified reported that the clinicians with scribes allocated to them had altered schedules which allowed them to see more patients per day. No emergency department studies discussed altering staffing ratios.

Though we did not identify any studies assessing virtual scribes, many vendors offer the service. Virtual scribes may be of increasing interest as they may allow for increased accessibility, especially in rural areas or in cases of a pandemic, as well as potentially save money as they can be used on-demand.^51^

Additional information on the role of medical scribes in primary care and other specialty settings was beyond the scope of our report and not included. However, these studies are typically of similar methodological quality to those identified in our report – that is, single-site reports with clinician volunteers, vendor supplied scribes, and limited outcome (including financial) reporting. Their results suggest modest effects for improving documentation time and patient satisfaction.^15^ It is not known how the results from these settings can be applied to future implementation in orthopedic, cardiology, and emergency departments. A prior systematic review identified 5 studies published through 2014 and noted limited quality and quantity of information.^16^

## LIMITATIONS

This review had several limitations. Evidence evaluating the effect of medical scribes was very limited and of poor methodological quality. Only 2 RCTs were identified, 1 conducted in Australia. Also, the bulk of the available evidence comes from 2 distinct groups, using the same general population in several studies and from single-site settings. There also was no reliable evidence available to address different aspects of a scribe program, such as quality of documentation and medical errors. Data on financial impacts was difficult to interpret, as most studies did not report the cost of initiation, implementation, or sustainability. Studies that used vendor services did not include the cost of these vendor services in their estimates of revenues. Variation in training programs and requirements put forth by scribe vendors was not well described. Measures used to quantify outcomes also varied widely across studies. There were also no data on the organizational structures and resources needed to develop and maintain scribe programs as well as barriers and facilitators to implementation.

### Applicability of Findings to the VA Population

Current findings have limited applicability and raise important questions about implementation, research gaps and future research. Despite information that there may be 100,000 medical scribes in the US in 2020,^17^ there is a paucity of data on the effectiveness, harms, costs, and quality of scribes, or on best methods for implementation and evaluation. No studies were conducted in Veterans Affairs Medical Centers and the effectiveness and financial productivity for widespread implementation across a national health care system are not known. Several reports were not from the US, and many evaluated programs after training had been completed and limited inclusion to clinicians volunteering for scribe services. Additionally, a large amount of information was reported from 2 emergency department groups, 1 in Australia. The only report from a cardiology department was limited to a single clinic in the US that assigned scribes to clinician volunteers and altered the daily schedule of clinicians working with scribes to permit more clinic visits. Scribes in the cardiology report were hired by an outside vendor and had extensive experience. Charges and costs for the services provided by the vendor were not described. None of the programs described the possible role of allocating scribe services to employees currently assigned other clinic duties, including administrative, nursing or “clinician extenders”. The effect of scribes on improving efficiency, patient access, and throughput likely also requires additional programmatic factors including reducing clinic appointment times and increasing the number of patients scheduled per day.

## RESEARCH GAPS/FUTURE RESEARCH

Our principal finding is that there are large gaps in evidence that require future research. Despite the marked increase in the use of medical scribes in the United States, there is no high-quality information evaluating their effects on clinic efficiency, health care access, patient or clinician satisfaction, or financial investment and productivity in cardiology, orthopedic and emergency departments. There are no data on the use of virtual scribes. Additionally, there are limited data on other important aspects of a medical scribe program, including documentation quality, the comparative effects of in-house versus contracted hiring, training, maintaining, and/or supervising, large-scale implementation of medical scribes, and other components to medical scribe programs required to enhance care quality, including productivity. Future research should be more transparent about costs related to contracting scribes through a vendor, as well as any administrative oversight costs that must exist even when using a vendor for scribes. Data from other clinical settings (primary care and other specialty clinics) is of limited applicability, quality, and quantity.

## POLICY IMPLICATIONS

Our results have policy implications and suggest that prior to widespread implementation, more information is needed on the effectiveness, harms, and costs of scribe programs. If information is deemed sufficient for programmatic rollout, then clear identification and evaluation of programmatic goals (improving access and patient/provider satisfaction, enhancing documentation quality, increasing clinical throughput), resources, programmatic models, and personnel required, as well as implementation barriers and facilitators, are needed.

## CONCLUSIONS

Based on mostly serious risk of bias reports, in-person medical scribes may improve clinic efficiency and improve financial productivity and revenue as measured by relative value units in emergency departments. The effects on clinic efficiency appear to be small in magnitude and dependent on the type and method of outcome assessment. Cost and financial productivity data do not include the cost of hiring, training, maintaining, and supervising scribes. Generalizability of findings outside the reported settings is limited. The effect of medical scribes in cardiology departments is uncertain. There is no information from orthopedic departments or VA Medical Centers, or on virtual scribes. There is little information on patient or clinician satisfaction, scribe documentation quality, or whether results vary by in-house versus contracted hiring and training.