# RESULTS

After removing duplicates, we identified 621 citations for title and abstract triage. A hand-search of systematic review bibliographies yielded 2 additional references. We reviewed the full text of 45 articles and identified 22 which met our inclusion criteria (Figure 1).

Of the eligible articles, we identified 2 observational studies from cardiology departments, both from the same group at a Minneapolis, MN-based health care system. No eligible articles were identified from orthopedic departments. (Table 2)

All but 2 eligible articles (20/22, 91%) were from emergency departments. Of these, 6 publications (all observational) came from the same group at a Rochester, MN-based health care system and 6 publications (1 RCT, 1 secondary analysis of the RCT data, 4 observational) came from a group based in Australia. The remaining 8 publications consisted of 1 RCT and 7 observational studies. One of these observational studies was conducted in Canada, and the remaining observational studies and RCT were conducted in the US. Summary characteristics of eligible publications can be found in Table 2.

Eighteen studies reported clinic efficiency, 5 patient satisfaction, 5 clinician satisfaction, 8 for financial productivity, 10 on relative value units (RVUs), 3 for quality of documentation, and 3 for cost/time of training. Only 4 reports noted 4 out of our 5 outcomes of interest and only 2 reported on 3 outcomes of interest. (Table 3) Our summary of assessment of “effectiveness” is based on statistical significance of the effects rather than an established or derived clinical magnitude of importance or estimates of precision derived from confidence intervals.

Most authors (8/12) reported using a vendor service which supplied, trained, and managed scribes. One Australian group used a vendor service for a pilot study (1 publication) and then implemented an in-house scribe program (4 publications). Two US-based groups implemented an in-house scribe program (6 publications from one group and 1 publication from another). One publication did not report any information on scribe training. The remaining 9 publications used a vendor service. While most publications (18/22) reported on components of how scribes were trained (eg, on-site training or classroom lecture), very few provided details about training programs or costs associated with training. Few studies reported scribe experience at baseline. No studies reported associated and peripheral costs with employing scribes (administration or management) or elements such as scribe turnover. All programs utilized “in person” rather than virtual or tele-scribes.

Five studies (including both RCTs) were rated as moderate ROB and 15 studies were rated as serious ROB. Two studies were rated as critical risk of bias and not analyzed further.

Figure 1 Literature Flow

Table 2 Summary characteristics of all eligible publications

Author, Year | Risk of Bias | Location | Outcomes Reported
Author, Year | Risk of Bias | Location | Clinic Efficiency (k=18) | Patient Satisfaction (k=5) | Clinician Satisfaction (k=5) | Financial productivity (k=8) | Relative Value Units (k=10) | Quality of Documentation (k=3) | Cost/Time of Training (k=3)
Orthopedics
No eligible studies identified
Cardiology
Bank, 2013 ^28^ | Critical | United States | X | X | | X | X
Bank, 2015 ^29^ | Serious | United States | X | | | X | X | X | X
Emergency Departments
Walker, 2014 ^30^ | Critical | Australia | X | | | X | | | X
Walker, 2016a ^31^ | Serious | Australia | X | X | X | X
Walker, 2016b ^32^ | Serious | Australia | | | | X
Walker, 2017 ^33^ | Moderate | Australia | | | | | | X
Dunlop 2018 ^34^ | Serious | Australia | X | X
Walker, 2019 * ^35^ | Moderate | Australia | X | | | X | | X | X
Heaton, 2016 ^36^ | Serious | United States | X | | | | X
Heaton, 2017a ^37^ | Serious | United States | X | | | | X
Heaton, 2017b ^38^ | Moderate | United States | | | | | X
Heaton, 2018 ^39^ | Serious | United States | X
Heaton, 2019a ^40^ | Serious | United States | | | | | X
Heaton, 2019b ^41^ | Serious | United States | X | | | X
Allen, 2014 ^42^ | Serious | United States | X | | X
Arya, 2010 ^43^ | Moderate | United States | X | | | | X
Bastani, 2014 ^44^ | Serious | United States | X | X
Friedson, 2018 * ^45^ | Moderate | United States | X | | | | X
Graves, 2018 ^46^ | Serious | Canada | X | | | X
Hess, 2015 ^47^ | Serious | United States | X | | X | | X
Ou, 2017 ^48^ | Serious | United States | X | | X
Shuaib, 2017 ^49^ | Serious | United States | X | X | X | | X

* Randomized controlled trial

Table 3 Summary of results for emergency department publications^*^

Author, Year; Risk of Bias | Outcomes
Author, Year; Risk of Bias | Patients per hour per clinician | Door-to-Room/Waiting Time (minutes) | Door-to-Provider (minutes) | Appointment Length/Time-to-disposition | Door-to-Discharge/LOS (minutes) | LWBS | Patient Satisfaction | Clinician Satisfaction | Financial Productivity | Relative Value Units (RVU)
Walker, 2016a ^31^; Serious | ↑; 1.13 vs 1.02 | NR | ↔ | NR | ↔ | NR | ↔ | ↔ | ↔ ^h^ | NR
Walker, 2019 ^35^; Moderate | ↑; 1.31 vs 1.13 | NR | ↔ | NR | ↓; 173 vs 192 | NR | NR | NR | ↑ ^i^; −$26.15/hr | NR
Dunlop 2018 ^34^; Serious | NR | NR | ↔ | NR | NR | NR | ↔ | NR | NR | NR
Heaton 2016 ^36^; Serious | ↔ | NR | ↔ | ↔ | ↑; 265 vs 255 | NR | NR | NR | NR | NR
Heaton 2017a ^37^; Serious | NR | NR | ↔ | ↔ | ↔ | NR | NR | NR | NR | NR
Heaton 2017b ^38^; Moderate | NR | NR | NR | NR | NR | NR | NR | NR | NR | ↑ ^k^; 4.04 vs 3.84
Heaton 2018 ^39^; Serious | NR | NR | NR | ↔ | NR | NR | NR | NR | NR | NR
Heaton 2019a ^41^; Serious | NR | NR | ↔ | ↔ | ↔ | NR | NR | NR | NR | ↔ ^k^
Heaton, 2019b ^40^; Serious | NR | NR | NR | NR | NR | NR | NR | NR | ↑ ^j^; $488 vs $600 | NR
Allen, 2014 ^42^; Serious | ↔ | ↔ | ↔ | ↓; 157 vs 169 | ↓; 233 vs 249 | ↔ | NR | + ^c^ | NR | NR
Arya, 2010 ^43^; Moderate | ↑; +1.63^a^ | NR | NR | NR | ↔ | NR | NR | NR | NR | ↑ ^l^; +0.24
Bastani, 2013 ^44^; Serious | NR | ↓; 34 vs 35 | ↓; 61 vs 74 | ↓; 185 vs 237 | ↓; 269 vs 289 | NR | ↑ ^b^; 58% vs 75% | ↑ ^d^; 62% vs 92% | NR | NR
Friedson, 2018 ^45^; Moderate | ↑; 2.33 vs 2.23 | NR | NR | ↓; 228 vs 258 | NR | NR | NR | NR | NR | ↔ ^m^; ↑ ^n^; 72 vs 77
Graves, 2018 ^46^; Serious | ↑; 2.81 vs 2.49 | NR | NR | NR | NR | NR | NR | NR | NR | NR
Hess, 2015 ^47^; Serious | ↔ | NR | NR | NR | ↔ | ↑ | NR | + ^e^ | NR | ↔/↑ ^o^
Ou, 2017 ^48^; Serious | NR | NR | NR | NR | NR | NR | NR | + ^f^ | NR | NR
Shuaib, 2017 ^49^; Serious | ↑; 3.2 vs 2.3 | ↓; 41 vs 37 | ↓; 56 vs 61 | ↓; 228 vs 237 | ↓; 287 vs 303 | NR | ↔ | ↑ ^g^; 66% vs 81% | NR | ↔ ^p^; ↑ ^q^; 241 vs 336

↔=no significant difference; ↑=increase in outcome compared to control group; ↓=decrease in outcome compared to control group; +=satisfaction reported, but no comparison group; LOS=length of stay; LWBS=left without being seen; NR=not reported; RVU=relative value units

* Numerical data only presented when deemed statistically significant

a Calculated by ESP team, unable to calculate for comparison group

b Press Ganey Survey: Overall patient satisfaction percentiles

c 100% clinicians reported “scribes are a valuable addition”; 77% clinicians reported “scribes increase workplace satisfaction; 90% clinicians reported “scribes increase quality of life”

d Press Ganey Survey: Overall physician satisfaction percentiles

e 62% clinicians “liked or loved working with scribes”, 74% clinicians “positive or very positive attitude towards scribes”, 82% clinicians “positive or very positive changes in efficiency”

f 85% residents “my interactions with attendings have improved with scribes”, 79% “scribes have improved my overall education as a resident in the emergency department”

g “Physician satisfaction increased 15% from pre- to post-scribe” (p=NR)

h Billing per patient

i “Cost saving to the hospital per scribed hour of $26.15 when hospital absorbs the cost of training”

j estimated costs of charting per shift

k mean RVUs per patient

l RVUs per hour increased by 0.24 units for every 10% increment in scribe usage during a shift

m total RVUs per shift

n trimmed RVUs per shift (lowest and highest 10% removed from analysis)

o Pre-post differences in seasonally-matched productivity metrics; mean differences in RVU per patient and RVU per hour were mixed

p mean RVUs per patient

q mean total RVUs per hour

## KEY QUESTION 1A WHAT IS THE EFFECT OF MEDICAL SCRIBES IN ORTHOPEDIC CLINICS?

We identified no eligible studies that examined the effect of medical scribes in orthopedic clinics.

## KEY QUESTION 1B WHAT IS THE EFFECT OF MEDICAL SCRIBES IN CARDIOLOGY CLINICS?

### Key Messages

- In cardiology clinics, the effect of medical scribes on efficiency and financial productivity is uncertain.
- There are no data on medical errors or scribe training (eg, time to train, turnover).
- Resources required to train, staff, maintain, and monitor scribes are substantial and rarely reported.
- There are no data on the role of scribes in VA cardiology clinics.

We identified 2 eligible studies that examined the effect of medical scribes in cardiology clinics.^28,29^ Both studies were conducted by the same group at a single center in St. Paul, Minnesota. One of these studies was rated critical ROB and not analyzed further.^28^ Detailed ROB assessments can be found in Appendix 4.

Bank et al^29^ performed a retrospective study comparing routine clinic visits of 10 cardiologists with scribes to 15 cardiologists without scribes. For physicians without scribes, patients were scheduled 20 minutes for follow-up and 40 minutes for new patient visits. Every 4 hours, one follow-up slot was left unscheduled for physicians to “catch up” with dictation/documentation. For physicians using scribes, the open 20-minute slot every 4 hours was eliminated; resulting in 22 and 24 scheduled patients per 8-hour day, in routine and scribe clinics respectively.

Scribes received approximately 184 hours of total training, including classroom lecture, supervised on-floor training, and cardiology-specific terminology and clinic processes from an outside “scribe vendor” hired to perform these services and provide ongoing monitoring and retention. Scribe duties included medical documentation services and clerical support.

Summary results are presented in Table 4. Detailed study characteristics and results can be found in Appendix Table 6-1 and Appendix Table 6-2, respectively. Certainty of evidence tables can be found in Appendix 7.

Table 4 Summary results for cardiology studies

Author, Year; Risk of Bias | Study Characteristics; (Sample size) | Outcomes
Author, Year; Risk of Bias | Study Characteristics; (Sample size) | Patients/hour per clinician | Patient Satisfaction | Clinician Satisfaction | Financial productivity | Relative Value Units
Bank, 2015^29^; Serious | Retrospective observational; N=25 providers | ↑; 2.5 vs 2.3 | NR | NR | ↑ | ↑ ^a^

↑=increase in outcome compared to control group; ↓=decrease in outcome compared to control group; NR=not reported

a work based on Relative Value Units

### Clinic Efficiency

Bank et al^29^ reported that physicians who had a scribe, and were thus scheduled for more patients per day (24 vs 22), saw more new (84) and returning (423) patients annually, but did not report any tests of statistical significance. Physicians with scribes saw 9.6% more patients per hour (2.5 vs 2.3) when compared to physicians without scribes (P=.01); however, by design scheduling templates for physicians with scribes allowed for more appointments.

### Patient/Clinician Satisfaction

No studies assessed patient or clinician satisfaction.

### Health Care and System Outcomes

#### Financial Productivity and Relative Value Units

Bank et al^29^ reported the use of scribes was associated with more patients seen annually, and an increase in work RVUs. Scribes’ clinic notes were coded and billed at a higher level. The study estimated an “additional annual revenue of $1,372,694 at a cost [for the scribes’ salary] of $98,588.” No data were provided on the costs paid to the vendor or other administrative or operating costs. The lead author was noted to be a paid consultant to 2 different scribe vendors, though not the vendor used for this study.

#### Quality of Documentation

While Bank et al^29^ did not formally evaluate the quality of documentation, they stated “the higher level of service associated with visits using a scribe suggests that documentation may be better during those visits.”

## KEY QUESTION 1C WHAT IS THE EFFECT OF MEDICAL SCRIBES IN EMERGENCY DEPARTMENTS?

### Key Messages

- The quality, quantity, completeness, and applicability of findings is limited.
- Medical scribes may improve efficiency by increasing number of patients seen per hour (low certainty of evidence [COE]) and decreasing length of stay (moderate COE). The magnitude of effect is likely small; efficiency may vary based on the setting and outcomes assessed.
- Medical scribes may increase revenues or RVUs due to more patients seen per hour (low COE); however, resources required to train, staff, maintain, and monitor scribes are substantial and rarely accounted for in these estimations.
  ○ Financial impacts varied based on how outcomes were measured.
- In emergency departments, medical scribes may make little to no difference in door-to-room or door-to-provider time, number of patients who left without being seen, and patient or clinician satisfaction, though results were mixed.
- No comparative reliable data on quality of documentation or medical errors was identified.
- There are no data on the role of scribes in VA emergency departments.

Twenty eligible studies were identified that reported on the effect of medical scribes in emergency departments.^30–49^ Six were from one group in Australia,^30–35^ 6 from one group in the US,^36–41^ and the remaining 8 were from different areas around the US^42–45,47–49^ and Canada.^46^

Two RCTs were identified^35,45^ and rated as moderate ROB. From the remaining observational studies, 3 were rated moderate ROB,^33,38,43^ 15 were rated serious ROB,^29,31–34,36,37,39–42,44,46,48,49^ and 2 were rated critical ROB and not analyzed further.^28,30^ Outcome reporting was incomplete and varied across studies. For example, no study reported on all our outcomes of interest and few reported on 3 or more. The most commonly reported outcomes were measures of clinic efficiency (16/20 studies), financial productivity (6/20) and RVU (8/20).

### Walker et al Group (Victoria, Australia)

Six studies, conducted by the Walker group, were included that assessed outcomes of interest in emergency department clinics. All studies were conducted at a private emergency department (ED) setting in Australia. Cabrini Hospital is a tertiary, non-profit, Catholic private hospital in southeast Melbourne. Therefore, results from this group are likely to be highly correlated across the studies, though are not considered duplicate reporting of results. The emergency department sees approximately 24,000 adult and pediatric patients annually and has a 48% admission rate.

One prospective observational pilot study was conducted in 2013,^30^ which was rated critical ROB and omitted for further analysis. An additional prospective pilot study was conducted in 2014,^31^ which was rated serious ROB. This study used a single American scribe provided by a scribe company that required 2 years of experience. The third study in this series was an economic evaluation describing the cost to implement an in-house training program, and train Australian scribes, which was rated serious ROB and did not provide any comparison data.^32^ A multi-center RCT was then conducted from 2015–2018, using the trained Australian scribes from the economic evaluation discussed previously; it was rated moderate ROB.^35^ The RCT was conducted at the same private emergency department, as well as other facilities within the same health care system. During the RCT period, a qualitative interview study was done to assess patient satisfaction, which was rated serious ROB.^34^ Using data from the RCT, a secondary analysis was conducted to assess note quality, which was rated moderate ROB.^33^

Detailed ROB assessments can be found in Appendix 4. Summary results for the 3 Walker studies that reported outcomes of interest are presented in Table 5. Detailed study characteristics can be found in Appendix Table 6-3 and detailed results for clinic efficiency, patient and clinician satisfaction, and health care systems outcomes can be found in Appendix Table 6-4, Appendix Table 6-5, and Appendix Table 6-6, respectively. Certainty of evidence tables can be found in Appendix 7.

Table 5 Summary results for emergency department studies (Walker group, Australia)^*^

Author, Year; Risk of Bias; Study Characteristics; (sample size) | Outcomes
Author, Year; Risk of Bias; Study Characteristics; (sample size) | Patients per hour per clinician | Door-to-Room/Waiting Time (minutes) | Door-to-Provider (minutes) | Appointment Length/Time-to-disposition | Door-to-Discharge/LOS (minutes) | LWBS | Patient Satisfaction | Clinician Satisfaction | Financial Productivity | Relative Value Units
Walker, 2016a ^31^; Serious; Prospective observational, single center; N=5 physicians; N=799 shifts; N=6344 patients | ↑; 1.13 vs 1.02 | NR | ↔ | NR | ↔ | NR | ↔ | ↔ | ↔ ^a^ | NR
Walker, 2019 ^35^; Moderate; RCT, multi-center; N=88 physicians; N=3885 shifts; N=28936 patients | ↑; 1.31 vs 1.13 | NR | ↔ | NR | ↓; 173 vs 192 | NR | NR | NR | ↑ ^b^; −$26.15/hour | NR
Dunlop 2018 ^34^; Serious; Semi-structured interview; N=215 patients | NR | NR | ↔ | NR | NR | NR | ↔ | NR | NR | NR

↔=no significant difference; ↑=increase in outcome compared to control group; ↓=decrease in outcome compared to control group; LOS=length of stay; LWBS=left without being seen; NR=not reported; RCT=randomized controlled trial

* Numerical data only presented when deemed statistically significant

a Billing per patient

b “Cost saving to the hospital per scribed hour of $26.15 when hospital absorbs the cost of training”

#### Clinic Efficiency

##### Patients seen per day

Two studies reported on the number of patients seen per day. One was a single center prospective cohort, rated serious ROB,^31^ and the other was a multicenter randomized controlled trial, rated moderate ROB.^35^ Both studies reported an increase in the total number of patients seen per hour in the scribe group when compared to the non-scribe group. However, the observational study did not report any tests of statistical significance. The RCT reported that scribes increased the number of patients seen per hour per clinician from 1.13 (95% CI 1.11 to 1.17) to 1.31 (95% CI 1.25 to 1.38), representing a 15.9 percent relative increase (P<0.001).

##### Door-to-provider time

Three studies reported on door-to-provider time. One was a single center prospective cohort, rated serious ROB,^31^ another was a multicenter randomized controlled trial, rated moderate ROB,^35^ and the third was a qualitative interview study conducted during the same time period as the RCT.^34^ None of these studies reported any significant difference in door-to-provider time in the scribe group compared to the non-scribe group.

##### Appointment length

None of the Walker et al studies reported on outcomes related to appointment length.

##### Time-to-disposition

None of the Walker et al studies reported on outcomes related to time-to-disposition.

##### Length of stay/Door-to-discharge time

Two studies reported on length of stay, though results were mixed. One was a single center prospective cohort, rated serious ROB,^31^ and the other was a multicenter randomized controlled trial, rated moderate ROB.^35^ The prospective cohort study reported no significant difference in length of stay between the scribe and non-scribe groups. Conversely, the RCT found that the length of stay in the scribe group was reduced by 19 minutes (absolute reduction) when compared to the non-scribe group (P<.001).

##### Patients left without being seen

None of the Walker et al studies reported on the number of patients who left the emergency department without being seen.

#### Patient/Clinician Satisfaction

Two studies reported on patient and/or clinician satisfaction. Both were conducted at the same private ED and rated serious ROB. One was a prospective cohort study which reported “no patients asked the scribe to leave or complained about the scribe’s presence” and “all physicians were satisfied with the initial history/physical exam capture into the chart and would like a scribe permanently.” However, no formal data collection measures were described.^31^

The second study was a qualitative, semi-structured interview study which reported no differences in patient satisfaction between the scribe and non-scribe groups. This study was conducted during the same time as the aforementioned RCT and consisted of interviewing patients while they were in the waiting room using previously validated questionnaires.^34^

#### Health Care and System Outcomes

##### Financial productivity and relative value units

Three studies reported on the financial impacts of implementing a scribe program. Two were single center prospective cohort studies both rated serious ROB,^31,32^ and the third was a multi-center RCT rated moderate ROB.^35^

Walker et al 2016a^31^ was a pilot study which reported no significant differences in amount billed per patient between the scribe group and the non-scribe group. The scribe group reported an average of billing $150 per patient, while the non-scribe group reported an average of billing $149 per patient. These estimates did not include the cost of the scribe.

Walker et al 2016b^32^ was an economic evaluation study conducted to determine the cost of implementing a scribe program. The medical center hired and trained scribes with no previous experience and measured recruitment costs, start-up costs, cost of training materials/courses, and administration costs of their scribe program. They found that scribes required 68–118 hours of training to become competent, and medical students achieved competency faster (after 7 shifts) than premedical students (after 8–16 shifts), and individuals from other disciplines did not achieve competency. The program took 7 months to implement (not including initial stakeholder buy-in time). Out of 79 applicants, 22 were invited to interview, and 10 had successful interviews. From those 10, only 5 (2 medical students and 3 pre-medical students) successfully completed training and became competent scribes.

Costs were reported based solely on a salary for the scribes ($15.91/hour), which included a 25% “on-cost” or “fringe”. Costs were reported for the total time it took to implement the scribe program (7 months) and does not include or report the amount of time for initial stakeholder buy-in or cost to replace departing scribes. (Table 6) The study also compared physicians’ productivity (based on patients seen per hour) with and without scribe trainees, and found that the productivity of physician trainers was unaffected while training scribes.

Table 6 Reported costs of implementing a scribe program from Walker et al^32^

Component | Total cost (US$) | Total cost per competent scribe^a^ (US$)
Recruitment and start-up | 15,555 | 3,111
Education program | 6,283 | 1,257
Administration | 4,326 | 866
Clinical training | 5,686 | 1,137
Total | 31,853 | 6,371

a at the end of the implementation, the institution had 5 competent scribes

Walker et al (2019)^35^ was a multi-center RCT that used the scribes trained in the previously described economic evaluation^32^ and estimated costs during the RCT period. The authors reported that scribes earned $20.51/hour and physicians earned $165/hour; estimating a 15% gain in productivity when a scribe was working generated a savings of $24.75/hour in physician time. The study also reported “training the scribe cost $5015 per scribe, and scribes worked 1000 hours once trained, generating a cost per hour worked of US$5 after completion of training.”

##### Quality of documentation

No study directly reported on quality of documentation.

However, 1 multicenter moderate ROB RCT^35^ reported 16 “incidents” (possibly attributed to the scribe) where the scribe was present and recorded. The majority of incidents related to patient identification and selecting the incorrect patient from the medical record. In all instances the error was corrected without further incident. The study also reported that “the presence of scribes at times worked as a protective factor in reducing medical error.” The rate of incidents reported where a scribe was present was one in every 300 encounters.

Analysis of notes taken during the above RCT^33^ found that the Physician Documentation Quality Instrument^50^ used to evaluate the quality of notes did not demonstrate reliability or validity. Authors also described difficulty is assessing note quality for accuracy considering evaluators weren’t in the room when the consultation took place. Additional information indicated that notes were longer in the scribe group (357 words) compared to the non-scribe group (237 words; P<.0001) but that there was no difference in their rate of omissions (42% vs 43%) or sufficiency of information to manage the patient (92% vs 93%).

### Heaton et al Group (Mayo, Rochester, MN)

Six studies, conducted by the Heaton group, were included that assessed outcomes of interest in emergency department clinics. Because they were all conducted at the same medical center and authored by the same group their findings are likely to be highly correlated across reports within this group (though not considered duplicate results reporting). All studies were prospective cohort studies conducted in the United States. Five studies were rated as serious risk of bias^36,37,39–41^ and 1 as moderate.^38^ The studies recruited and trained scribes using an in-house training program that was developed by a physician with prior experience with scribes. Detailed ROB ratings can be found in Appendix 4.

Two of the studies reported grant^39^ or hospital funding.^41^ The studies varied by study period as well as the primary objectives. Scribes were recruited and trained through an in-house training program with a defined curriculum developed by a physician with prior experience implementing scribe programs. Individuals who agreed to participate in the studies included attending physicians,^36–41^ residents,^37,38^ senior resident physicians,^36–38,41^ nurse practitioners,^36–38^ physician assistants,^36–38^ and interns.^41^

In all studies scribe duties included medical documentation services and clerical support. Most scribes were college students or recent graduates with an interest in health science careers. A summary of reported outcomes is presented in Table 7. Detailed study characteristics can be found in Appendix Table 6-7 and detailed results clinic efficiency and health care system outcomes can be found in Appendix Table 6-8 and Appendix Table 6-9, respectively. Certainty of evidence tables can be found in Appendix 7.

Table 7 Summary results for emergency department studies (Heaton group, MN)^*^

Author, Year; Risk of Bias; Study Characteristics; (sample size) | Outcomes
Author, Year; Risk of Bias; Study Characteristics; (sample size) | Patients per hour per clinician | Door-to-Room/Waiting Time (minutes) | Door-to-Provider (minutes) | Appointment Length/Time-to-disposition | Door-to-Discharge/LOS (minutes) | LWBS | Patient Satisfaction | Clinician Satisfaction | Financial Productivity | Relative Value Units (RVU)
Heaton 2016 ^36^; Serious; Prospective Cohort; N=8015 patients | ↔ | NR | ↔ | ↔ | ↑; 265 vs 255 | NR | NR | NR | NR | NR
Heaton 2017a ^37^; Serious; Prospective Cohort; N=6119 patients | NR | NR | ↔ | ↔ | ↔ | NR | NR | NR | NR | NR
Heaton 2017b ^38^; Moderate; Prospective Cohort; N=39926 visits | NR | NR | NR | NR | NR | NR | NR | NR | NR | ↑ ^a^; 4.04 vs 3.84
Heaton 2018 ^39^; Serious; Prospective Cohort; N=48 shifts | NR | NR | NR | ↔ | NR | NR | NR | NR | NR | NR
Heaton 2019a ^41^; Serious; Prospective Cohort; N=4629 patients | NR | NR | ↔ | ↔ | ↔ | NR | NR | NR | ↔ ^a^ | NR
Heaton 2019b ^40^; Serious; Prospective Cohort; N=8 shifts | NR | NR | NR | NR | NR | NR | NR | NR | NR | ↑ ^b^; $488 vs $600

↔=no significant difference; ↑=increase in outcome compared to control group; ↓=decrease in outcome compared to control group; LOS=length of stay; LWBS=left without being seen; NR=not reported

* Numerical data only presented when deemed statistically significant

a mean RVUs per patient

b estimated costs of charting per shift

#### Clinic Efficiency

##### Patients seen per day

One report from this group, rated as serious risk of bias, reported outcomes related to patients seen per day.^36^ The study reported no difference in patients seen per hour among attending physicians with a scribe compared with no scribe; however, no data was provided.

##### Door-to-provider time

Three reports from this group reported outcomes related to door-to-provider time in the emergency department.^36,37,41^ All studies were rated as serious risk of bias.

All studies found median door-to-provider time to be similar in scribe and non-scribe groups, with time ranging from 20 to 25 minutes in the scribe group and 19 to 27 minutes in the non-scribe group. Heaton 2017a^37^ and Heaton 2016^36^ also found similar times between groups among attending physicians, second- and third-year residents, nurse practitioners, and physician assistants. Additionally, Heaton 2019^41^ also compared door-to-provider times in morning, afternoon, and overnight shifts. The study found door-to-provider time to be shorter in the scribe group (21 minutes) compared to the non-scribe group (28 minutes) during overnights shifts (P=.01) but similar during morning and afternoon shifts.

##### Appointment length

Four reports from this group reported outcomes related to appointment length.^36,37,39,41^ All studies were rated as serious risk of bias. Three studies found time in treatment room to be similar in scribe and non-scribe groups, with time ranging from 176 to 222 minutes in the scribe group and 181 to 221 in the non-scribe group.^36,37,41^ Heaton 2017^37^ and Heaton 2016^36^ also found similar times between groups in attendings, second- and third-year residents, nurse practitioners, and physician assistants, while Heaton 2019b^41^ found similar treatment room times in morning, afternoon, and overnight shifts.

Heaton 2018^39^ reported time spent at patient bedside. Based on 24 shifts, the average time was found to be similar between scribe and non-scribe groups (138 versus 140 minutes, P=.88).

##### Time to disposition

Three reports from this group, rated as serious risk of bias, reported outcomes related to disposition time.^36,37,41^ None found a difference between scribe and non-scribe groups. Two studies reported that the median provider-to-disposition time among patients were similar between scribe and non-scribe groups (P=.51 and P=.32).^37,41^ The third study also found median provider-to-disposition times among providers were similar between groups (P=.15).^36^

##### Length of stay/Door-to-discharge time

Three studies, rated as serious risk of bias, reported outcomes related to length of stay.^36,37,41^ Outcomes were mixed. Two studies reported median length of stay among patients and found it to be similar between scribe and non-scribe groups, 215 versus 214 minutes (P=.34) and 267 versus 272 minutes (P=.34).^37,41^ In comparison, the third study found median length of stay among clinician s to be greater in the scribe group, 265 versus 255 minutes (P=.03).^36^

##### Patients left without being seen

The Heaton group did not report on outcomes related to the number of patients who left without being seen.

#### Patient/Clinician Satisfaction

None of the Heaton group’s eligible articles reported patient or clinician satisfaction regarding the use of medical scribes in the emergency department.

#### Health Care and System Outcomes

##### Financial productivity and relative value units

Three studies reported outcomes related to cost or revenue. One study was rated as moderate risk of bias^38^ and the other 2 as serious risk of bias.^40,41^ Results were mixed.

Heaton 2017^38^ estimated the mean RVUs per patient to be higher in the scribe group compared to the non-scribe group (4.04 vs 3.84 per patient [mean difference [MD] 0.20, P<.001]). In post hoc analyses they also found RVUs to be higher in the scribe group among patients with emergency severity levels of 2 and 3 (P<.001) but similar among severity levels of 1, 4, and 5 (P value ranges from .10 to 0.63). RVUs were also higher in chest pain, heart, and respiratory emergencies (P<.001); ear, throat, and nose emergencies (P=.04); leg fractures (P=0.027); and psychiatric emergencies (P=.002). In comparison, patients in the scribe group had lower RVUs in vision emergencies (P=.027).

Heaton 2019^41^ estimated the mean RVUs were similar between scribe and non-scribe groups, 4.79 versus 4.72 (P=.76).

One study reported the cost of charting per shift.^40^ The cost of a physician per clinical hour was estimated to be $200 and the cost of a scribe was $11. For every 3 hours, the study estimated costs to be $488 in the scribe group (accounting for 2 hours of clinical work and 1 hour of scribe work) compared to $600 in the non-scribe group.

##### Other health care and systems outcomes

The Heaton group did not report any outcomes related to time to train scribes, turnover of scribes, medical errors, or quality of documentation.

### Other Publications (United States and Canada)

Eight additional studies were included that assessed outcomes of interest in emergency department clinics.^42–49^ Seven studies were pre-post design and 1 was a randomized controlled trial.^45^ One study instituted an in-house 60-hour training program and required 2 years of clerical experience.^43^ Six additional studies used outside vendors to employ and train scribes, One company considered scribes to be proficient after 15 shifts and skilled after 45 shifts^47^ while another company considered scribes to be proficient after 20 shifts and skilled after 40 shifts.^49^ Six of the 7 pre-post studies were rated as serious risk of bias and 1 was rated as moderate risk of bias.^43^ The single randomized controlled trial was rated as moderate risk of bias.

Seven studies were conducted in the United States^42–45,47–49^ and 1 in Canada.^46^ Of the 2 studies that reported funding, 1 was funded by hospital and foundation,^46^ the other by foundation and industry.^45^

Six studies employed scribes using independent scribe companies responsible for hiring and training.^44–49^ One trial instituted a 60-hour training program and required scribes to have 2 years of experience.^43^ One study considered scribes skilled after 45 shifts^47^ and another after 40 shifts.^49^

In all studies scribe duties included medical documentation services and clerical support. Most scribes were college students or recent graduates with an interest in health science careers. The number of clinicians included in the studies ranged from 26 to 103, and scribe to doctor ratio was typically 1 to 1.

Detailed ROB assessments can be found in Appendix 4. A summary of reported outcomes is presented in Table 8. Detailed study characteristics can be found in Appendix Table 6-10 and detailed results for clinic efficiency, patient and clinician satisfaction, and health care system outcomes can be found in Appendix Table 6-11, Appendix Table 6-12 and Appendix Table 6-13, respectively. Certainty of evidence tables can be found in Appendix 7.

Table 8 Summary results for emergency department studies (US and Canada)^*^

Author, Year; Risk of Bias | Outcomes
Author, Year; Risk of Bias | Patients per hour per clinician | Door-to-Room/Waiting Time (minutes) | Door-to-Provider (minutes) | Appointment Length/Time-to-disposition | Door-to-Discharge/LOS (minutes) | LWBS | Patient Satisfaction | Clinician Satisfaction | Financial Productivity | Relative Value Units
Allen, 2014 ^42^; Serious; Retrospective Cohort (pre-post); N=NR | ↔ | ↔ | ↔ | ↓; 157 vs 169 | ↓; 233 vs 249 | ↔ | NR | + | NR | NR
Arya, 2010 ^43^; Moderate; Retrospective Cohort (pre-post); N=243 shifts | ↑; +1.63^a^ | NR | NR | NR | ↔ | NR | NR | NR | | ↑ ^a^; +0.24
Bastani, 2013 ^44^; Serious; Prospective Cohort (pre-post); N=24,338 patients | NR | ↓; 34 vs 35 | ↓; 61 vs 74 | ↓; 185 vs 237 | ↓; 269 vs 289 | NR | ↑ ^b^; 58% vs 75% | ↑ ^c^; 62% vs 92% | NR | NR
Friedson, 2018 ^45^; Moderate; RCT; N=905 shifts | ↑; 2.33 vs 2.23 | NR | NR | ↓; 228 vs 258 | NR | NR | NR | NR | NR | ↔ ^d^; ↑ ^e^; 72 vs 77
Graves, 2018 ^46^; Serious; Prospective Cohort (pre-post); N=158 shifts | ↑; 2.81 vs 2.49 | NR | NR | NR | NR | NR | NR | NR | NR | NR
Hess, 2015 ^47^; Serious; Prospective Cohort (pre-post); N=103 providers | ↔ | NR | NR | NR | ↔ | ↑ | NR | + ^f^ | NR | ↔/↑ ^g^
Ou, 2017 ^48^; Serious; Qualitative survey; N=47 residents | NR | NR | NR | NR | NR | NR | NR | +^h^ | NR | NR
Shuaib, 2017 ^49^; Serious; Prospective Cohort (pre-post); N=23,319 encounters | ↑; 3.2 vs 2.3 | ↓; 41 vs 37 | ↓; 56 vs 61 | ↓; 228 vs 237 | ↓; 287 vs 303 | NR | ↔ | ↑ ^i^; 66% vs 81% | NR | ↔ ^j^; ↑ ^k^; 241 vs 336

↔=no significant difference; ↑=increase in outcome compared to control group; ↓=decrease in outcome compared to control group; +=satisfaction reported, but no comparison group; LOS=length of stay; LWBS=left without being seen; NR=not reported; RCT=randomized controlled trial

* Numerical data only presented when deemed statistically significant

a RVUs per hour increased by 0.24 units for every 10% increment in scribe usage during a shift

b Press Ganey Survey: Overall patient satisfaction percentiles

c Press Ganey Survey: Overall physician satisfaction percentiles

d total RVUs per shift

e trimmed RVUs per shift (lowest and highest 10% removed from analysis)

f 62% clinicians “liked or loved working with scribes”, 74% clinicians “positive or very positive attitude towards scribes”, 82% clinicians “positive or very positive changes in efficiency”

g Pre-post differences in seasonally-matched productivity metrics; mean differences in RVU per patient and RVU per hour were mixed

h 85% residents “my interactions with attendings have improved with scribes”, 79% “scribes have improved my overall education as a resident in the emergency department”

i “Physician satisfaction increased 15% from pre- to post-scribe” (p=NR)

j mean RVUs per patient

k mean total RVUs per hour

#### Clinic Efficiency

##### Patients seen per day/hour/shift

Six studies reported outcomes related to patients seen per day, per hour or per shift. Five studies were pre-post^42,43,46,47,49^ and 1 was a randomized controlled trial.^45^ Four of the studies were rated as serious risk of bias, and 2 were rated as moderate^.43,45^ Results generally suggested that scribes were associated with an increase in the number of patients seen per day, per hour or per shift.

One RCT^45^ found that the number of patients per shift increased with scribes compared to non-scribed shifts, 18.6 per clinician per shift versus 17.8 (MD=0.8, P<.05). Four pre-post studies also found an increase in patients seen per provider shift or per day^43,46,47,49^ One study found no difference in the number of registered visits seen with and without a scribe (MD=−0.99, P=.47).^42^

Additionally, 1 study conducted a post-only survey in which 77% of residents stated that scribes allow them to see more patients.^48^

##### Door-to-room time/waiting time

Three pre-post studies reported on outcomes related to emergency department waiting time. Results were mixed. All studies were rated as serious risk of bias.^42,44,49^ One study found door-to-room waiting time to be less in scribed cohorts compared to non-scribed cohorts, 37 versus 41 minutes (P<.0001).^49^ A second study found door-to-room waiting time to be similar between scribe and non-scribe cohorts in the total cohort (MD=−0.01; P=.65). However, the study found door-to-room waiting time to be lower with scribes among admitted patients (MD=0.02; P=.001).^42^ A third study also found waiting time to be similar between groups, 34 versus 35 minutes.^44^

Two studies reported room-to-provider times.^44,49^ One study found room-to-provider time to be less in the scribe cohort compared to the non-scribe cohort, 24 versus 26 minutes (P<.0001).^49^ The second reported room-to-provider waiting time to 31 minutes in the scribe group and 39 minutes in the non-scribe group.^44^

Additionally, 1 study reported door-to-triage waiting time and found it to be less with a scribe (MD=−0.01; P=.008).^42^ Door-to-triage waiting time was also found to be less with a scribe among admitted patients (MD=0.02; P<.001) but not among discharged patients (MD=0; P=.20).

##### Door-to-provider time

Three pre-post studies, rated as serious risk of bias, reported mean door-to-provider time in the emergency department.^42,44,49^ Door-to-provider time is defined as the time elapsed from when the patient arrives in the ED until the physician signs on to the patient’s chart. Results were mixed.

Two studies found door-to-provider time to be significantly lower in the scribe group compared to the non-scribe group. Bastani et al^44^ reported door-to-provider time to be 61 minutes with a scribe versus 74 minutes without a scribe (P<.0001). Shuaib et al^49^ reported 56 minutes with a scribe versus 61 minutes without a scribe (P<.0001).

However, the third study did not find a significant difference between the scribe and non-scribe groups, reporting 1.28 mean hours (76.8 minutes) with a scribe versus 1.34 (80.4 minutes) mean hours without a scribe (P=.07).^42^

##### Appointment length/Time-to-disposition

Four studies reported mean provider-to-disposition time, defined as the time elapsed from when the physician signs on to the patient’s chart to the time the patient is discharged or admitted.^42,44,45,49^ All 4 studies reported lower mean provider-to-disposition time in the scribe group compared to the non-scribe group. Three of these studies were pre-post prospective cohort studies and rated as serious ROB.

The first study reported provider-to-disposition time to be shorter with a scribe compared to without a scribe, 228 versus 237 minutes (P<.0001).^49^ The second study also found provider-to-disposition time to be shorter in the scribe cohort, 2.61 versus 2.82 minutes (MD=−0.21; P<.001). This difference was found in both admitted (MD=−0.38; P<.0001) and discharged patients (MD−0.09; P=.021).^42^ The third study reported the average provider-to-disposition time to be 185 minutes in the scribe cohort and 237 minutes in the non-scribe cohort (P<.0001).^44^ The fourth study was a randomized controlled trial, rated as moderate risk of bias.^45^ The trial found provider-to-disposition time was shorter in the scribe group compared to the non-scribe group, 3.8 mean hours (228 minutes) versus 4.3 (258 minutes) (P<.01).

Shuaib et al^49^ conducted a time-motion analysis of provider activities, breaking down different parts of a patient visit. Chart prep, chart review, and post-visit documentation were all found to be significantly lower in the post-scribe group (P<.01), while physical examination time was similar between groups. The study found doctor-patient interaction time to be greater in the scribe cohort compared to the non-scribe cohort, 7.8 mean minutes versus 4.0 (P<.01).

##### Length of stay/Door-to-discharge time

Five pre-post studies reported outcomes related to time spent in the emergency department and length of stay. Four studies were rated serious ROB^42,44,47,49^ and 1 was rated moderate.^43^ Results were mixed.

One study defined “length of stay” as the time between arrival of the patient and departure from ED.^47^ Two other studies used the term “length of stay”, but did not define it further.^44,49^ One study referred to this as “turn-around-time”, defined as the difference between electronically generated arrival and discharge times.^43^ Of these 4 studies, 2 reported length of stay to be significantly lower in the post-scribe group, while the other 2 reported the pre-and-post mean length of stay to be similar between groups. Shuaib et al^49^ found the length of stay, on average, to be shorter in the scribe cohort among both admitted patients, 473 minutes versus 507 minutes (P<.0001) and discharged patients, 287 minutes versus 303 (P<.0001). Bastani et al^44^ also reported length of stay, on average, to be shorter in the post-scribe cohort in both admitted, 442 minutes versus 448 (P<.0001), and discharged patients, 269 minutes versus 289 (P<.0001). Comparatively, the Hess et al^47^ found length of stay to be similar between scribe and non-scribe cohorts (MD=0.14 [95% CI −0.05, 0.33; P=.15]). Arya et al^43^ reported turn-around-times (in minutes) were not significantly affected by scribe usage, when scribes were utilized in 10% increments during a shift (0.4 [95% CI −5.3, 6.1; P=.88]). The fifth study reported average door-to-exit time, defined as the time elapsed from when a patient arrives in the ED to the time the patient exits the ED, was greater in the pre-scribe cohort compared to the post-scribe cohort, 5.76 hours (345.6 minutes) versus 5.62 (337.2 minutes) (P=.021).^42^ The study found the average door-to-exit time to be greater among admitted patients in the post-scribe group, 8.27 mean hours(496.2 minutes) versus 7.61 (456.6 minutes; MD=0.65, P<.0001); however the time was shorter among discharged patients (4.89 hours/293.4 minutes versus 5.07 hours/304.2 minutes; MD=−0.18; P=.01). This study also reported door-to-disposition time, defined as the time elapsed from when the patient arrived in the ED until the clinician decided a patient’s disposition. Allen et al reported, on average, a shorter door-to-disposition time with scribes compared to without scribes, 3.89 (233.4 minutes) versus 4.16 (249.6 minutes) hours (MD=−0.27; P<.0001). The difference was also found among discharged (MD=−0.16; P=.03) and admitted (MD=−0.38; P<.0001) patients.

##### Patients left without being seen

Two pre-post studies reported on the number of patients that left without being seen. Both studies were rated as serious risk of bias.^42,47^ Results were mixed.

Hess 2015 reported a greater number of patients left without being seen in the scribe cohort compared to non-scribe cohort, 4.41 versus 2.94 (1.47 [95% CI 0.83, 2.11; P<.01]), while Allen 2014 found no difference in scribe and non-scribe cohorts, 5% versus 5% (P=.38).

#### Patient Satisfaction

Two pre-post studies, rated as serious risk of bias, reported patient satisfaction with mixed results. Using a Likert scale (1=poor to 5=excellent), Shuaib et al^49^ asked 6 questions: 1) the doctor carefully listened to concerns; 2) the doctor explained things in a way you can understand; 3) meticulousness of examination; 4) doctors instructions concerning follow-up care; 5) the doctor was courteous; and 6) the doctor provided satisfactory feedback to questions. Results were similar for questions 1–5 for the pre-and-post scribe groups. However, the sixth question had higher scores in the post-scribe group compared to the pre-scribe group, 4.7 versus 3.9 (P<.01).^49^

Using the Press Ganey Survey, the second pre-post study found ‘patient satisfaction’ increased from the 58th percentile in the pre-scribe group to the 75th percentile in the post-scribe group.^44^

#### Clinician Satisfaction

Five studies reported on clinician satisfaction. All studies were rated as serious risk of bias. Two studies conducted surveys pre-and-post scribes,^44,49^ 1 conducted pre-and-post surveys with additional post-only questions^48^ and 2 conducted post-only surveys to measure clinician satisfaction.^42,47^ Of the 3 that conducted pre-and-post surveys, 1 reported an increase in clinician satisfaction using the Press Ganey Survey from the 62^nd^ percentile to the 92^nd^ percentile in the pre-and-post scribe groups, respectively.^44^ Another reported that physician satisfaction increased from 66% to 81% in the pre-and-post scribe groups, respectively, but did not provide further information about how it was measured.^49^ The third study was a survey study measuring resident perceptions of their educational experience before and after a scribe program implementation.^48^ Ou et al^48^ conducted a pre-and-post survey, and additional questions post survey. Only 1 question from the pre-and-post survey was significantly different between groups, “I have enough fact-to-face teaching with the attendings during my shift”. Of the 47 residents surveyed, 17% agreed to this statement during the pre-scribe survey and 55% agreed during the post-scribe survey (p<.001). Among the 47 resident clinicians, 85% reported “my interaction with attendings have improved with the implementation of scribes” and 79% reported “scribes have improved my overall education as a resident in the emergency department” in the post-only survey.

Among the 2 studies that provided post-only data, both reported clinicians were satisfied with the implementation of a scribe program. Hess et al^47^ reported that among 71 providers, 62% “liked or loved working with scribes”; 74% had an “overall positive or very positive attitude toward scribes”; and 82% experienced “positive or very positive changes in efficiency”. Allen et al^42^ reported that among 20 providers, 100% agreed with the statement, “scribes are a valuable addition”, 67% agreed with “scribes increase workplace satisfaction”, and 89% agreed with “scribes increase quality of life”.

#### Health Care and System Outcomes

##### Financial productivity and relative value units

One randomized controlled trial^45^ and 4 pre-post studies^43,46,47,49^ reported outcomes related to financial impacts. The randomized controlled trial was rated as moderate risk of bias, 3 studies as serious risk, and 1 study as moderate risk.^43^ In general, scribes were associated with a positive financial impact, though none of the studies reported on the cost of the contracted services required to hire, train, maintain, and supervise scribes.

The randomized controlled trial reported total RVUs between scribe and non-scribe groups. Total RVUs were similar between scribe and non-scribe groups, 76.5 versus 7.3 (MD=2.14; P=non-significant; no numerical value reported). However, after excluding shifts with the highest and lowest 10% of RVUs from analysis, total RVUs were greater in the scribe group, 76.9 versus 72.0 (MD=4.87; P<.01).^45^

In the first pre-post study, the average costs of a clinician amounted to $1200 per shift ($150 per hour) and the average costs of scribes were estimated to be $216 per shift ($27 per hour). The study assessed that “given a scribe may be associated with a mean increase of 13% in productivity ‘costs’ to a physician using a scribe would be about $60 relative to what their earning without a scribe would be”. The study suggested a greater income with scribes even after accounting for associated scribing costs.^46^

The second study found RVUs per patient to be similar between scribe and non-scribe groups, 2.74 versus 2.57 (P=.88). However, the study found RVUs per hour to be greater in the scribe group compared to the non-scribe group, 336 versus 241 (P<.001).^49^

The third study compared a 4-month period (September-December 2011) before scribe implementation to the same 4-month period (September-December 2012) after the scribe implementation. The study found mean RVUs per hour to be greater in the scribe group, though small in magnitude in September (MD=0.00008; P=.03), October (MD=0.00016; P<.01), and November (MD=0.0001; P=.03), but similar in December (MD=0.00003,P=.57). Mean RVUs per patient were also assessed between scribe and non-scribe groups. RVUs per patient were greater in the scribe group in October (MD=0.00007; P<.01) but similar in September (MD=0.00001; P=.39), November (MD=0.0; P=.98), and December (MD=−0.00003; P=.08).^47^

The fourth pre-post study reported an additional 24 RVUs per 10-hour shift with the use of scribes (P=.00011).^43^

## KEY QUESTION 2 HOW DO THE EFFECTS OF MEDICAL SCRIBES VARY BASED ON DIFFERENCES IN COMPENSATION STRUCTURE, QUALIFICATIONS, TYPES OF ENTRIES, OR SETTING?

### Summary of Findings

#### Key Messages

- No eligible studies were identified that reported if the effects of medical scribes varied based on differences in compensation structure, qualifications, types of entries, or other scribe-permitted tasks or scribe-specific qualifications, or setting within orthopedic or cardiology clinics.
- No eligible studies were identified that reported if the effects of medical scribes varied based on differences in compensation structure, types of entries, or other scribe-permitted tasks or scribe specific qualifications within emergency departments.
- Evidence was insufficient to determine whether the effect of medical scribes on emergency department efficiency varied based on clinician training, experience, or area of service within the emergency department.

Very few articles were identified (k=5) that addressed how the effects of medical scribes vary based on provider qualifications and setting. Additionally, no studies compared scribes employed and contracted by outside vendors to those trained and employed by medical institutions. Summary characteristics of the scribe training programs for each eligible study can be found in Table 9. All studies required additional on-the-job training regardless of the hiring mechanism.

Table 9 Summary characteristics of scribe training programs

Author, Year | Risk of Bias | Location | Training Supplied by: | | Total Training | Experience | Training Characteristics
Author, Year | Risk of Bias | Location | In-house | Vendor | Total Training | Experience | Classroom lecture | On-line/training manual | On-floor training | Supervised scribing
Orthopedics
No eligible studies identified
Cardiology
Bank, 2015 ^29^ | Serious | United States | | X | 184 hours | 6 years | X | | X | X
Emergency Department
Walker, 2016a ^31^ | Serious | Australia | | X | NR | 2 years | NR
Walker, 2016b ^32^ | Serious | Australia | X | | 68–118 | None | | X | X | X
Walker, 2017 ^33^ | Moderate | Australia | X | | 68–118 | None | | X | X | X
Dunlop 2018 ^34^ | Serious | Australia | X | | 68–118 | None | | X | X | X
Walker, 2019* ^35^ | Moderate | Australia | X | | 68–118 | None | | X | X | X
Heaton, 2016 ^36^ | Serious | United States | X | | NR | NR | | X | X | X
Heaton, 2017a ^37^ | Serious | United States | X | | NR | NR | | X | X | X
Heaton, 2017b ^38^ | Moderate | United States | X | | NR | NR | | X | X | X
Heaton, 2018 ^39^ | Serious | United States | X | | NR | NR | | X | X | X
Heaton, 2019a ^40^ | Serious | United States | X | | NR | NR | | X | X | X
Heaton, 2019b ^41^ | Serious | United States | X | | NR | NR | | X | X | X
Allen, 2014 ^42^ | Serious | United States | NR | | NR | NR | NR
Arya, 2010 ^43^ | Moderate | United States | X | | 60 hours | NR | | | | X
Bastani, 2014 ^44^ | Serious | United States | | X | NR | NR | NR
Friedson, 2018* ^45^ | Moderate | United States | | X | NR | NR | NR
Graves, 2018 ^46^ | Serious | Canada | | X | NR | NR | | | X | X
Hess, 2015 ^47^ | Serious | United States | | X | NR | NR | | | X | X
Ou, 2017 ^48^ | Serious | United States | | X | 6–8 weeks | NR | X | | X | X
Shuaib, 2017 ^49^ | Serious | United States | | X | NR | NR | | | X | X

NR=not reported

### Emergency Department: Walker et al Group (Victoria, Australia)

#### Clinic Efficiency

##### Patients seen per hour

Walker 2016a^31^ assessed the number of patients seen per hour for 5 individual doctors with and without a scribe. A 9–15% relative increase was reported, varying by doctor, but did not provide any further detail about specific physicians’ qualifications or experience that may account for these varying effects. The article concluded it would be more cost-effective to allocate scribes to faster doctors.

Walker et al (2019)^35^ assessed the number of patients seen per hour per doctor by different regions of the emergency department. No significant differences were found during sub-acute, fast-track, or observation ward shifts. A small but statistically significant increase was reported for “acute” shifts, (increase of 0.09 (0.03 to 0.15) patients per hour per doctor), and larger increase for “senior doctor at triage” shifts, (increase of 0.53 (0.14 to 0.93) patients per hour per doctor).

### Emergency Department: Heaton et al Group (Mayo, Rochester, MN)

#### Clinic Efficiency

##### Provider-to-disposition

Heaton 2016^36^ assessed provider-to-disposition time by training experience and found no difference between scribe and non-scribe groups among attending physicians, year-2 residents, year-3 residents, and nurse practitioners or physician assistants. Heaton 2017 also assessed provider to disposition time by clinic area and found no difference between scribe and non-scribe groups in areas seen by attending physicians with residents (P=.21) or attending physicians with nurse practitioners or physician assistants (P=.42).

Heaton 2019^41^ also assessed provider-to-disposition time among patients by time of shift. They study found median disposition times were similar between groups in morning (189 minutes in non-scribe group vs 179) and afternoon (223 minutes in non-scribe group vs 224) shifts but higher in the scribe group in overnight shifts (146 minutes in non-scribe group vs 156) (P=.01).

##### Length of stay

Heaton 2016^36^ assessed length of stay by training experience and found no difference between scribe and non-scribe groups among attending physicians (P=.06), year-2 residents (P=.55), and nurse practitioners or physician assistants (P=.39). However, length of stay was shorter among patients seen by year-3 residents, 244 versus 262 minutes (P=.02).

Heaton 2017^37^ assessed length of stay by clinic area and found no difference between scribe and non-scribe groups in areas seen by attending physicians with residents (P=.18) or attending physicians with nurse practitioners or physicians assistants (P=.80).

Heaton 2019^41^ assessed length of stay among patients by time of shift. They study found median disposition times were similar between groups in morning (P=.13), afternoon (P=.86), and overnight (P=.86) shifts.