# METHODS

## TOPIC DEVELOPMENT

Section 507 of the 2018 VA MISSION Act has mandated a 2-year medical scribes pilot in specialty and emergency departments within VA. This pilot will evaluate the impact of medical scribes on clinician efficiency, patient volume, and patient satisfaction within cardiology, orthopedic, and emergency department clinics. This review was convened to supplement findings from this pilot to inform future use of medical scribes in VA. Key Questions (KQ) were developed in collaboration with stakeholders from the VA Office of Nursing Services, along with our technical expert panel.

1. What is the effect of medical scribes in cardiology, orthopedic, or emergency department clinics?
2. How do the effects of medical scribes vary based on differences in compensation structure (ie, contracted through vendor or employees of the institution), qualifications (ie, training, accreditation, experience), types of entries (ie, medical orders, medical history, coding [billing, diagnoses, complexity/comorbidities]), or setting (ie, rural, urban, access-challenged)?

A protocol was developed with input from stakeholders and our Technical Expert Panel and registered in PROSPERO (CRD42020169079).

## DATA SOURCES & SEARCHES

We searched MEDLINE, EMBASE, and CINAHL from 2010 through December 2019 using Medical Subject Headings (MeSH) and keywords for medical scribes and outcomes of interest (Appendix 1). We supplemented these results with additional searches of bibliographies from recent systematic reviews, and references from our technical expert panel.

## STUDY SELECTION

Eligible citations were screened independently by 2 reviewers using Distiller SR (Distiller SR, Evidence Partners, Ottawa, Canada) with prespecified criteria. Citations moved to full-text review if either reviewer considered the citation eligible. At full-text review, agreement of 2 reviewers was needed for study inclusion or exclusion; disputes were resolved by discussion with input from a third reviewer, if needed.

We included English-language intervention studies, interrupted time series or other pre-post studies, and observational studies comparing participation in a medical scribe intervention to usual care or no intervention. Only adult patients and/or practitioners in cardiology, orthopedic, or emergency departments were considered eligible for inclusion. Eligible interventions consisted of a “medical scribe” or “document assistant” program that involved navigation of an electronic health record system and provided some information about scribe responsibilities/duties. Eligible studies reported outcomes related to clinic efficiency (eg, patients seen per hour, length of stay), clinician and/or patient satisfaction, financial impacts (eg, revenues, cost of scribes), quality of documentation, medical errors, or scribe training (eg, time to train, turnover). A full list of inclusion/exclusion criteria can be found in Appendix 2.

## DATA ABSTRACTION & STUDY QUALITY ASSESSMENT

We formally assessed risk of bias (ROB) of each individual study by assessing critical elements using the ROBINS-I tool^13^ for observational studies and a modified Cochrane tool^14^ for randomized controlled trials (RCTs), as described in Appendix 3. Two reviewers independently rated each non-randomized eligible study as low, moderate, serious, or critical ROB, and randomized studies were rated as low, moderate, or high ROB. Consensus was reached through discussion, if necessary. Studies rated as critical or high ROB were not included for analysis. Ratings for each study can be found in Appendix 4.

We abstracted data from all eligible studies with low, moderate, or serious ROB on: design and description of study; health care setting (rural, urban, access-challenged); scribe duties (types of entries); clinician and scribe experience; scribe training and/or accreditation (hours of training and whether training was in-house or contracted by a vendor); quality of documentation and/or medical errors; baseline characteristics including age, gender; number of patients admitted (for emergency department studies); funding source; and all data related to outcomes of interest (ie, clinic efficiency, patient/clinician satisfaction, and financial impacts). For clinic efficiency, we abstracted number of patients seen per hour or shift, door-to-room time, door-to-provider time, length of appointments, length of stay/door-to-disposition time, and number of patients who left without being seen (for emergency room studies). For financial productivity we abstracted revenues and costs related to scribe training.

We also abstracted relative value units (RVUs), which are a measure of physician and health system productivity and used by Medicare for reimbursement. Each medical procedure has a number of RVUs associated with it, and payment per RVU can vary depending on a number of factors, such as the local price level and the local malpractice environment. In 2020, the monetary value to be reimbursed per RVU was $36.0896.^24^

## DATA SYNTHESIS & ANALYSIS

Due to heterogeneity of populations and interventions, data were not pooled but narratively synthesized. Tables were developed by outcome and stratified by clinical setting (ie, cardiology or emergency department). For Key Question 2, our subgroups of interest included: compensation structure (ie, contracted through a vendor or employee of the institution), qualifications, duties and type of entry required, and setting.

Overall quality of evidence for the primary outcomes considered ‘critical’ (important for decision making) within each comparison was evaluated using a modified Grading of Recommendations Assessment, Development and Evaluation (GRADE) approach on 5 assessed domains.^25^ The quality of evidence levels range from high to very low (Table 1). The 5 domains include: (1) study limitations (risk of bias); (2) directness (single, direct link between intervention and outcome); (3) consistency (similarity of effect direction and size among studies); (4) precision (degree of certainty around an estimate [ie, width of confidence intervals]); and (5) publication bias. In the GRADE approach, the initial quality of evidence is considered high for RCTs and low for observational studies.^26,27^ Our summary of assessment of “effectiveness” is based on statistical significance of the effects rather than an established or derived clinical magnitude of importance or estimates of precision derived from confidence intervals.

We graded certainty of evidence for the following outcomes that we deemed critical to decision making: patients seen per hour, length of stay, patient satisfaction, clinician satisfaction, and RVUs.

Table 1 GRADE Quality of Evidence

GRADE Quality of Evidence Levels
Quality Level | Definition
High | We are very confident that the true effect lies close to that of the estimate of the effect.
Moderate | We are moderately confident in the effect estimate: The true effect is likely to be close to the estimate of the effect, but there is a possibility that is substantially different.
Low | Our confidence in the effect estimate is limited: The true effect may be substantially different from the estimate of the effect.
Very Low | We have very little confidence in the effect estimate: The true effect is likely to be substantially different from the estimate of the effect.

## PEER REVIEW

A draft version of this report was reviewed by 4 technical experts and VA operational partners. Their comments and our responses are presented in Appendix 5.