# INTRODUCTION

Medical scribes are individuals who assist health care clinicians (physicians, nurse practitioners, and physician assistants) with day-to-day tasks including recording and documenting information in real-time during patient visits.^1,2^ In addition to documenting medical visits, primary medical scribe duties and responsibilities include communicating with patients and completing clerical tasks; verifying and correcting mistakes or inconsistencies in medical records; collecting, organizing, and cataloging data for clinicians; and attending trainings related to practice.^1^ Medical scribes are most commonly unlicensed individuals with a health-degree focus^2^; however, accreditation programs do exist. Integrating medical scribes with clinicians is suggested to improve access, quality and timeliness of care, enhance patient and clinician satisfaction, and increase clinician productivity and health system revenue.^3–5^

Medical scribe use has increased markedly in the past 10 years making it the fastest-growing health care profession in the United States.^2^ This increase is believed to result, in part, from implementation of Electronic Medical Records (EMRs) required by legislation. In 2009 the Health Information Technology for Economic and Clinical Health (HITECH) Act, part of the American Recovery and Reinvestment Act (ARRA), was enacted and required meaningful use of health information technology.^2^ These acts created a large demand for electronic data entry by health care clinicians as well as an increase in documentation requirements for billing and reporting initiatives.^2^

EMRs provide important advantages, such as structural and process-related benefits^6^ and enhanced patient care.^7^ However, EMRs increase the burden of clinical documentation, disrupt face-to-face encounters with patients,^8^ and reduce time available for resident and student training.^9^ Additionally, efficiency measures required by the quality reporting program enacted by the Centers for Medicare & Medicaid Services (CMS), such as door-to-doctor time or length of stay, have increased pressure on clinicians and health systems to meet these quality metrics.^10^

While formal training, accreditation, and recertification are not required for all scribe positions, there are 2 scribe accreditation programs in the United States from the American College of Medical Scribe Specialist and the American Healthcare Documentation Professional Group. Both accreditation programs test aspiring scribes on competencies related to care and require completed pre-clinical training as well as clinical training hours.^18,19^ The American College of Medical Scribe Specialists is also certified by CMS and emphasizes CMS reporting in the training.^20^ Both programs require re-training and licensing every 12–24 months.

Scribes are typically hourly employees with wages ranging from $10 to $21 per hour.^21^ Costs to consider before implementing a scribe program may include salary, taxes, and benefits. Although some larger scribe vendors may provide health insurance, many individual clinicians and health institutions do not.^22^ When implementing scribes though in-house hiring and training programs, previous studies have put internal recruitment costs of scribes around $3,117 per scribe and additional training costs around $1,200.^23^

Alternatively, contracting scribes through external vendors is also an option. Companies can be hired by health care systems or individual clinical groups to train, accredit, place, and conduct performance evaluations of scribes through contracting mechanisms to health care systems. These companies can reduce administrative hiring, training, and oversight burden to health care facilities and serve as a resource to replace scribes due to relatively high turnover. Additionally, these companies can also contract for “virtual scribes” whereby the scribes are located “off-site” and conduct their duties through video teleconferencing.^11^ To date there is little non-industry evidence comparing benefits, harms, and costs of contract (ie, vendor-supplied) scribes to those which are employees of the institution.

Within the Department of Veterans Affairs, the 2018 MISSION Act aimed to increase Veterans access to health care in VA facilities and the community. Section 507 of the MISSION Act^12^ mandates a 2-year pilot of in-clinic medical scribes in VA specialty clinics and emergency departments across the United States. The pilot will evaluate clinician efficiency, patient volume, and patient satisfaction.

We conducted a systematic review of the effects of medical scribes. With insight from our operational partners and technical expert panel members, our scope focused on outpatient emergency, cardiology, and orthopedic departments. The Section 507 Committee will use the findings of this review alongside findings from the medical scribe pilot to inform the use of medical scribes in VA including considerations of budgeting, resource utilization, and services where medical scribes may be most beneficial.