# APPENDIX 7 CERTAINTY OF EVIDENCE TABLES

Appendix Table 7.1 Certainty of Evidence Tables for Cardiology Studies

Appendix Table 7.2 Certainty of Evidence Tables for Emergency Department Studies: Randomized Controlled Trials

Appendix Table 7.3 Certainty of Evidence Tables for Emergency Department Studies: Observational Studies