# APPENDIX 6 EVIDENCE TABLES

Appendix Table 6-1 Characteristics of Cardiology Studies

Appendix Table 6-2 Reported Outcomes from Cardiology Studies

Appendix Table 6-3 Characteristics of Emergency Department Studies, Walker Group (Australia)

Appendix Table 6-4 Clinic Efficiency Reported Outcomes from Emergency Department Studies, Walker Group (Australia)

Appendix Table 6-5 Patient and Provider Satisfaction Reported Outcomes from Emergency Department Studies, Walker Group (Australia)

Appendix Table 6-6 Health care and System Reported Outcomes from Emergency Department Studies, Walker Group (Australia)

Appendix Table 6-7 Characteristics of Emergency Department Studies, Heaton Group (United States)

Appendix Table 6-8 Clinic Efficiency Reported Outcomes from Emergency Department Studies, Heaton Group (United States)

Appendix Table 6-9 Health care and System Reported Outcomes from Emergency Department Studies, Heaton Group (United States)

Appendix Table 6-10 Characteristics of Emergency Department Studies

Appendix Table 6-11 Clinic Efficiency Reported Outcomes from Emergency Department Studies

Appendix Table 6-12 Patient and Provider Satisfaction Reported Outcomes from Emergency Department Studies

Appendix Table 6-13 Health care and System Reported Outcomes from Emergency Department Studies