# APPENDIX 5 PEER REVIEW COMMENTS/AUTHOR RESPONSES

Question | Reviewer Number | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described? | 1 | Yes | Thank you.
Are the objectives, scope, and methods for this review clearly described? | 2 | Yes | Thank you.
Are the objectives, scope, and methods for this review clearly described? | 3 | Yes | Thank you.
Are the objectives, scope, and methods for this review clearly described? | 4 | Yes | Thank you.
Is there any indication of bias in our synthesis of the evidence? | 1 | No | Thank you.
Is there any indication of bias in our synthesis of the evidence? | 2 | No | Thank you.
Is there any indication of bias in our synthesis of the evidence? | 3 | No | Thank you.
Is there any indication of bias in our synthesis of the evidence? | 4 | No | Thank you.
Are there any published or unpublished studies that we may have overlooked? | 1 | No | Thank you.
Are there any published or unpublished studies that we may have overlooked? | 2 | No | Thank you.
Are there any published or unpublished studies that we may have overlooked? | 3 | No | Thank you.
Are there any published or unpublished studies that we may have overlooked? | 4 | No | Thank you.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 1 | Nice job on this! The executive summary could use another round of proofreading. | Thank you for the comment, we have proofread the executive summary and made edits as necessary.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 2 | Suggested changes, subtle and at the authors discretion.; Page 2, line 50: Data was not pooled; rather narratively synthesized.; Page 3, line 32: Are the quotations necessary?; Page 3, line 41: Take out and and make separate sentence thereafter.; Feels run on.; Page 3, line 45: KQ1 not previously defined and never is. Needs to be now or before introducing. | Thank you for the suggestions, edits have been made as appropriate.; The Key Questions are initially introduced at the end of the introduction on page 1–2.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | Recommended edits:; p. ii, line 36- correct credentials, Storm Morgan, MSN, MBA, RN; p. 4, line 30- “in” appears to be an extra word; p.5, line 24 and p.42, line 14–15. Word through put should be one word; p. 8, line 9–10- nurse practitioners are a form of advanced practice nurses so listing both entries seems unusual. I expected to see physicians, nurse practitioners, and physician assistants.; p. 34, line 8–9- Is the forward slash correct for 7.61/(456.6 mins)? | Thank you for the suggestions, edits have been made as appropriate.