# APPENDIX 4 QUALITY ASSESSMENT FOR ELIGIBLE PUBLICATIONS

## 4.1 NON-RANDOMIZED STUDIES

Author, Year | Bias due to confounding | Bias in selection of participants | Bias in classification of interventions | Bias due to deviations for intended interventions | Bias due to missing data | Bias in measurement of outcomes | Bias in selection of the reported result | Overall
Allen, 2014 ^42^ | Serious | Serious | Low | No information | Serious | Moderate | Moderate | Serious
Arya, 2010 ^43^ | Moderate | Moderate | Moderate | Moderate | Low | Low | Moderate | Moderate
Bank, 2013 ^28^ | Moderate | Critical | Moderate | Moderate | Moderate | Low | Low | Critical
Bank, 2015 ^29^ | Serious | Moderate | Moderate | Moderate | Moderate | Moderate | Moderate | Serious
Bastani, 2014 ^44^ | Serious | Serious | Moderate | No information | No information | Moderate | Moderate | Serious
Dunlop, 2018 ^34^ | Serious | Moderate | Low | Low | Low | Low | Low | Serious
Graves, 2018 ^46^ | Serious | Moderate | Low | Low | Low | Low | Low | Serious
Heaton, 2016 ^36^ | Serious | Low | Low | Low | Low | Moderate | Moderate | Serious
Heaton, 2017a ^37^ | Serious | Low | Low | No information | Low | Moderate | Moderate | Serious
Heaton, 2017b ^38^ | Moderate | Low | Low | Low | Low | Low | Low | Moderate
Heaton, 2018 ^39^ | Serious | Moderate | Low | No information | No information | Serious | Moderate | Serious
Heaton, 2019a ^41^ | Serious | Moderate | Low | No information | Low | Low | Moderate | Serious
Heaton, 2019b ^40^ | Serious | Moderate | Low | No information | No information | Low | Moderate | Serious
Hess, 2015 ^47^ | Serious | Serious | Low | No information | Serious | Moderate | Moderate | Serious
Ou, 2017 ^48^ | Serious | Serious | Low | No information | No information | Serious | Moderate | Serious
Shuaib, 2017 ^49^ | Serious | Moderate | Moderate | Moderate | No information | Moderate | Moderate | Serious
Walker, 2014 ^30^ | Critical | Critical | Moderate | Moderate | Moderate | Moderate | Moderate | Critical
Walker, 2016a ^31^ | Serious | Moderate | Moderate | Moderate | Moderate | Moderate | Moderate | Serious
Walker, 2016b ^32^ | Serious | Moderate | Moderate | Moderate | Moderate | Moderate | Moderate | Serious
Walker, 2017 ^33^ | Moderate | Moderate | Low | Moderate | Moderate | Moderate | Moderate | Moderate

## 4.2 RANDOMIZED CONTROLLED TRIALS

Author, Year | Random Sequence generation: | Allocation concealment | Blinding of personnel and participants: | Blinding of outcome assessment: | Incomplete outcome data | Selective outcome reporting | Other | Overall
Friedson, 2018 ^45^ | Low | Unclear | High | Low | Low | Low | None | Moderate
Walker, 2019 ^35^ | Low | Low | High | Low | Low | Low | None | Moderate