# APPENDIX 3 QUALITY ASSESSMENT CRITERIA

## 3.1 RISK OF BIAS IN NON-RANDOMIZED STUDIES – OF INTERVENTIONS (ROBINS-I)^13^

Bias due to confounding
Low | Moderate | Serious | Critical
(the study is comparable to a well-preformed randomized trial with regard to this domain); No confounding expected. | (the study is sound for a nonrandomized study with regard to this domain but cannot be considered comparable to a well-performed randomized trial); (i) Confounding expected, all known important confounding domains appropriately measured and controlled for;; and; (ii) Reliability and validity of measurement of important domains were sufficient, such that we do not expect serious residual confounding. | (the study has some important problems); (i) At least one known important domain was not appropriately measured, or not controlled for;; or; (ii) Reliability or validity of measurement of an important domain was low enough that we expect serious residual confounding. | (the study is too problematic to provide any useful evidence on the effects of intervention); (i) Confounding inherently not controllable; or; (ii) The use of negative controls strongly suggests unmeasured confounding.
Bias in selection of participants into study
Low | Moderate | Serious | Critical
(the study is comparable to a well-preformed randomized trial with regard to this domain); (i) All participants who would have been eligible for the target trial were included in the study;; and; (ii) For each participant, start of follow up and start of intervention coincided. | (the study is sound for a nonrandomized study with regard to this domain but cannot be considered comparable to a well-performed randomized trial); (i) Selection into the study may have been related to intervention and outcome; and the authors used appropriate methods to adjust for the selection bias;; or; (ii) Start of follow-up and start of intervention do not coincide for all participants;; and; (a) the proportion of participants for which this was the case was too low to induce important bias;; or; (b) the authors used appropriate methods to adjust for the selection bias;; or; (c) the review authors are confident that the rate (hazard) ratio for the effect of intervention remains constant over time. | (the study has some important problems); (i) Selection into the study was related (but not very strongly) to intervention and outcome; and This could not be adjusted for in analyses;; or; (ii) Start of follow up and start of intervention do not coincide; and A potentially important amount of follow-up time is missing from analyses; and the rate ratio is not constant over time. | (the study is too problematic to provide any useful evidence on the effects of intervention); (i) Selection into the study was very strongly related to intervention and outcome; and This could not be adjusted for in analyses;; or; (ii) A substantial amount of follow-up time is likely to be missing from analyses; and the rate ratio is not constant over time.
Bias in classification of interventions
Low | Moderate | Serious | Critical
(the study is comparable to a well-preformed randomized trial with regard to this domain); (i) intervention status is well defined;; and; (ii) Intervention definition is based solely on information collected at the time of intervention. | (the study is sound for a nonrandomized study with regard to this domain but cannot be considered comparable to a well-performed randomized trial); (i) Intervention status is well defined;; and; (ii) Some aspects of the assignments of intervention status were determined retrospectively. | (the study has some important problems); (i) Intervention status is not well defined;; or; (ii) Major aspects of the assignments of intervention status were determined in a way that could have been affected by knowledge of the outcome. | (the study is too problematic to provide any useful evidence on the effects of intervention); (Unusual) An extremely high amount of misclassification of intervention status, e.g. because of unusually strong recall biases.
Bias due to deviations from intended intervention
Low | Moderate | Serious | Critical
(the study is comparable to a well-preformed randomized trial with regard to this domain); [underlined: Effect of assignment to intervention:]; (i) Any deviations from intended intervention reflected usual practice;; or; (ii) Any deviations from usual practice were unlikely to impact on the outcome.; [underlined: Effect of starting and adhering to intervention:]; The important co-interventions were balanced across intervention groups, and there were no deviations from the intended interventions (in terms of implementation or adherence) that were likely to impact on the outcome. | (the study is sound for a nonrandomized study with regard to this domain but cannot be considered comparable to a well-performed randomized trial); [underlined: Effect of assignment to intervention:]; There were deviations from usual practice, but their impact on the outcome is expected to be slight.; [underlined: Effect of starting and adhering to intervention:]; (i) There were deviations from intended intervention, but their impact on the outcome is expected to be slight.; or; (ii) The important co-interventions were not balanced across intervention groups, or there were deviations from the intended interventions (in terms of implementation and/or adherence) that were likely to impact on the outcome; and The analysis was appropriate to estimate the effect of starting and adhering to intervention, allowing for deviations (in terms of implementation, adherence and co-intervention) that were likely to impact on the outcome. | (the study has some important problems); [underlined: Effect of assignment to intervention:]; There were deviations from usual practice that were unbalanced between the intervention groups and likely to have affected the outcome.; [underlined: Effect of starting and adhering to intervention:]; (i) The important co-interventions were not balanced across intervention groups, or there were deviations from the intended interventions (in terms of implementation and/or adherence) that were likely to impact on the outcome;; and; (ii) The analysis was not appropriate to estimate the effect of starting and adhering to intervention, allowing for deviations (in terms of implementation, adherence and cointervention) that were likely to impact on the outcome. | (the study is too problematic to provide any useful evidence on the effects of intervention); [underlined: Effect of assignment to intervention:]; There were substantial deviations from usual practice that were unbalanced between the intervention groups and likely to have affected the outcome.; [underlined: Effect of starting and adhering to intervention:]; (i) There were substantial imbalances in important cointerventions across intervention groups, or there were substantial deviations from the intended interventions (in terms of implementation and/or adherence) that were likely to impact on the outcome;; and; (ii) The analysis was not appropriate to estimate the effect of starting and adhering to intervention, allowing for deviations (in terms of implementation, adherence and cointervention) that were likely to impact on the outcome.
Bias due to missing data
Low | Moderate | Serious | Critical
(the study is comparable to a well-preformed randomized trial with regard to this domain); (i) Data were reasonably complete;; or; (ii) Proportions of and reasons for missing participants were similar across intervention groups;; or; (iii) The analysis addressed missing data and is likely to have removed any risk of bias. | (the study is sound for a nonrandomized study with regard to this domain but cannot be considered comparable to a well-performed randomized trial); (i) Proportions of and reasons for missing participants differ slightly across intervention groups;; and; (ii) The analysis is unlikely to have removed the risk of bias arising from the missing data. | (the study has some important problems); (i) Proportions of missing participants differ substantially across interventions; or Reasons for missingness differ substantially across interventions;; and; (ii) The analysis is unlikely to have removed the risk of bias arising from the missing data;; or Missing data were addressed inappropriately in the analysis;; or the nature of the missing data means that the risk of bias cannot be removed through appropriate analysis. | (the study is too problematic to provide any useful evidence on the effects of intervention); (i) (Unusual) There were critical differences between interventions in participants with missing data;; and; (ii) Missing data were not, or could not, be addressed through appropriate analysis.
Bias in measurement of outcomes
Low | Moderate | Serious | Critical
(the study is comparable to a well-preformed randomized trial with regard to this domain); (i) The methods of outcome assessment were comparable across intervention groups;; and; (ii) The outcome measure was unlikely to be influenced by knowledge of the intervention received by study participants (i.e. is objective) or the outcome assessors were unaware of the intervention received by study participants;; and; (iii) Any error in measuring the outcome is unrelated to intervention status. | (the study is sound for a nonrandomized study with regard to this domain but cannot be considered comparable to a well-performed randomized trial); (i) The methods of outcome assessment were comparable across intervention groups;; and; (ii) The outcome measure is only minimally influenced by knowledge of the intervention received by study participants;; and; (iii) Any error in measuring the outcome is only minimally related to intervention status. | (the study has some important problems); (i) The methods of outcome assessment were not comparable across intervention groups;; or; (ii) The outcome measure was subjective (i.e. vulnerable to influence by knowledge of the intervention received by study participants); and the outcome was assessed by assessors aware of the intervention received by study participants;; or; (iii) Error in measuring the outcome was related to intervention status. | (the study is too problematic to provide any useful evidence on the effects of intervention); The methods of outcome assessment were so different that they cannot reasonably be compared across intervention groups.
Bias in selection of the reported result
Low | Moderate | Serious | Critical
(the study is comparable to a well-preformed randomized trial with regard to this domain); There is clear evidence (usually through examination of a pre-registered protocol or statistical analysis plan) that all reported results correspond to all intended outcomes, analyses and subcohorts. | (the study is sound for a nonrandomized study with regard to this domain but cannot be considered comparable to a well-performed randomized trial); (i) The outcome measurements and analyses are consistent with an a priori plan; or are clearly defined and both internally and externally consistent;; and; (ii) There is no indication of selection of the reported analysis from among multiple analyses;; and; (iii) There is no indication of selection of the cohort or subgroups for analysis and reporting on the basis of the results. | (the study has some important problems); (i) Outcomes are defined in different ways in the methods and results sections, or in different publications of the study;; or; (ii) There is a high risk of selective reporting from among multiple analyses;; or; (iii) The cohort or subgroup is selected from a larger study for analysis and appears to be reported on the basis of the results. | (the study is too problematic to provide any useful evidence on the effects of intervention); (i) There is evidence or strong suspicion of selective reporting of results;; and; (ii) The unreported results are likely to be substantially different from the reported results.

## 3.2 COCHRANE RISK OF BIAS ASSESSMENT^14^

Domains | Low | Unclear | High
Randomization generation; Allocation concealment; Blinding of participants and personnel; Blinding of outcome assessors; Incomplete outcome data; Selective reporting | Plausible bias unlikely to seriously alter the results. | Plausible bias that raises some doubt about the results. | Plausible bias that seriously weakens confidence in the result