# APPENDIX 2 STUDY SELECTION

| Inclusion Criteria | | Exclusion Criteria
Population | Adult patients and/or practitioners in cardiology, orthopedic or emergency department clinics; EXCEPTION: Study done in within VA, even if it is primary care or another specialty | | Must be medical clinic (exclude OR, cardiac cath or laboratory settings); Exclude studies in trauma service settings; Exclude Primary care clinics (please tag); Exclude studies involving only children or pediatric clinics; studies including adults and children must stratify results based on age
Intervention | “Medical scribe” or document assistant program that involves navigation of electronic health record system (must provide some information about scribe responsibilities/duties). | | “Medical scribe” or “documentation assistant” programs that don’t involve an electronic medical record system Medical transcriptionist or documentation assistant programs that work remotely or transcribe based on physician recordings
Comparator | Any | | Studies without a comparison
Outcomes | [underlined: Primary:]; Clinic efficiency (as measured by):; # patients seen per day; time to consult; time to appt; appointment length; ED waiting times; time in ED (time to hospital admission or discharge to home); left without being seen in ED | [underlined: Secondary:]; Patient satisfaction; Practitioner satisfaction; Quality of documentation; Cost (expenses [scribe-related costs] and revenues [RVU, etc]); Time needed to train scribes; Scribe turnover; Medical errors
Timing | Any | | Published prior to 2010
Setting | Any location (to include government, private, university-affiliated, and VA facilities worldwide)

ED=emergency department; OR=operating room; RVU=relative value units