# APPENDIX 1 SEARCH STRATEGIES

## 1.1 OVID MEDLINE AND EMBASE

1 | (scrib* and (throughput or productivity or quality or errors or satisfaction or attitude or interaction or RVU or contact time or revenue or cost or turnover)).ti,ab. | 786
2 | (scrib* or transcriber* or documentation assistant*).mp. | 4066
3 | (emr or ehr or “medical record*” or “health record*”).mp. | 628093
4 | exp medical records systems, computerized/ or electronic health records/ | 53008
5 | 2 and (3 or 4) | 316
6 | 1 or 5 | 942
7 | Limit 6 to English language | 914
8 | limit 7 to yr=“2010 -Current” | 754
9 | remove duplicates from 8 | 537

## 1.2 CINAHL

1 | TI (scrib* and (throughput or productivity or quality or errors or satisfaction or attitude or interaction or RVU or contact time or revenue or cost or turnover) OR AB (scrib* and (throughput or productivity or quality or errors or satisfaction or attitude or interaction or RVU or contact time or revenue or cost or turnover) | 119
2 | TI (scrib* or transcriber* or documentation assistant*) OR AB (scrib* or transcriber* or documentation assistant*) | 475
3 | MW ( (emr or ehr or “medical record*” or “health record*”or medical records systems, computerized/ or electronic health records/ ) | 42181
4 | 2 and 3 | 57
5 | 1 or 4 | 155