# ABBREVIATIONS TABLE

Abbreviation: Definition
ARRA: American Recovery and Reinvestment Act
CI: Confidence interval
CMS: Centers for Medicare and Medicaid Services
COE: Certainty of evidence
ED: Emergency department
EMR: Electronic Medical Record
ESP: Evidence Synthesis Program
GRADE: The Grading of Recommendations Assessment, Development and Evaluation Approach
HITECH: Health Information Technology for Economic and Clinical Health Act
KQ: Key Question
MD: Mean difference
MeSH: Medical subject heading
RCT: Randomized controlled trial
ROB: Risk of bias
RVU: Relative value units
TEP: Technical expert panel
US: United States of America
VA: Department of Veterans Affairs