# REFERENCES

1 Litz BT, Stein N, Delaney E, Moral injury and moral repair in war veterans: a preliminary model and intervention strategy. Clin Psychol Rev. 2009;29(8):695–706. doi:10.1016/j.cpr.2009.07.003 19683376
2 Nieuwsma JA, O’Brien EC, Xu H, Smigelsky MA, Meador KG. Patterns of Potential Moral Injury in Post-9/11 Combat Veterans and COVID-19 Healthcare Workers. J Gen Intern Med. 2022;37(8):2033–2040. doi:10.1007/s11606-022-07487-4 35381899
3 Shay J. Moral injury. Psychoanal Psychol. 2014;31(2):182–191. doi:10.1037/a0036090
4 Jordan AH, Eisen E, Bolton E, Nash WP, Litz BT. Distinguishing war-related PTSD resulting from perpetration- and betrayal-based morally injurious events. Psychol Trauma Theory Res Pract Policy. 2017;9(6):627–634. doi:10.1037/tra0000249
5 Wisco BE, Marx BP, May CL, Moral injury in U.S. combat veterans: Results from the national health and resilience in veterans study. Depress Anxiety. 2017;(csp, 9708816). doi:10.1002/da.22614
6 Steenkamp MM, Litz BT, Hoge CW, Marmar CR. Psychotherapy for Military-Related PTSD: A Review of Randomized Clinical Trials. JAMA. 2015;314(5):489. doi:10.1001/jama.2015.8370 26241600
7 Shay J. The trials of homecoming: Odysseus returns from Iraq/Afghanistan. Smith Coll Stud Soc Work. 2009;79(3–4):286–298. doi:10.1080/00377310903130332
8 Koenig HG, Youssef NA, Pearce M. Assessment of Moral Injury in Veterans and Active Duty Military Personnel With PTSD: A Review. Front Psychiatry. 2019;10(101545006):443. doi:10.3389/fpsyt.2019.00443 31316405
9 Frankfurt S, Frazier P. A review of research on moral injury in combat veterans. Mil Psychol. 2016;28(5):318–330. doi:10.1037/mil0000132
10 Houle SA, Ein N, Gervasio J, Measuring moral distress and moral injury: A systematic review and content analysis of existing scales. Clin Psychol Rev. 2023;108(cnx, 8111117):102377. doi:10.1016/j.cpr.2023.102377 38218124
11 Hodgson TJ, Carey LB. Moral Injury and Definitional Clarity: Betrayal, Spirituality and the Role of Chaplains. J Relig Health. 2017;56(4):1212–1228. doi:10.1007/s10943-017-0407-z 28526912
12 Richardson NM, Lamson AL, Smith M, Eagan SM, Zvonkovic AM, Jensen J. Defining Moral Injury Among Military Populations: A Systematic Review. J Trauma Stress. 2020;33(4):575–586. doi:10.1002/jts.22553 32567119
13 Litz BT, Kerig PK. Introduction to the Special Issue on Moral Injury: Conceptual Challenges, Methodological Issues, and Clinical Applications. J Trauma Stress. 2019;32(3):341–349. doi:10.1002/jts.22405 31162737
14 Jinkerson JD, Battles AR. Relationships between moral injury syndrome model variables in combat veterans. Traumatology. 2019;25(1):33–40. doi:10.1037/trm0000163
15 Battles AR, Bravo AJ, Kelley ML, White TD, Braitman AL, Hamrick HC. Moral injury and PTSD as mediators of the associations between morally injurious experiences and mental health and substance use. Traumatology. 2018;24(4):246–254. doi:10.1037/trm0000153
16 Litz, B. T., Walker, H.E. Moral Injury: An Overview of Conceptual, Definitional, Assessment, and Treatment Issues. Annu Rev Clin Psychol. Published online Accepted for publication.
17 Hall NA, Everson AT, Billingsley MR, Miller MB. Moral injury, mental health and behavioural health outcomes: A systematic review of the literature. Clin Psychol Psychother. 2022;29(1):92–110. doi:10.1002/cpp.2607 33931926
18 McEwen C, Alisic E, Jobson L. Moral injury and mental health: A systematic review and metaanalysis. Traumatology. 2021;27(3):303–315. doi:10.1037/trm0000287
19 Bryan AO, Bryan CJ, Morrow CE, Etienne N, Ray-Sannerud B. Moral injury, suicidal ideation, and suicide attempts in a military sample. Traumatology. 2014;20(3):154–160. doi:10.1037/h0099852
20 Bryan CJ, Bryan AO, Roberge E, Leifker FR, Rozek DC. Moral injury, posttraumatic stress disorder, and suicidal behavior among National Guard personnel. Psychol Trauma Theory Res Pract Policy. 2018;10(1):36–45. doi:10.1037/tra0000290
21 Hayden JA, van der Windt DA, Cartwright JL, Côté P, Bombardier C. Assessing Bias in Studies of Prognostic Factors. Ann Intern Med. 2013;158(4):280. doi:10.7326/0003-4819-158-4-201302190-00009 23420236
22 Jacobs P, Viechtbauer W. Estimation of the biserial correlation and its sampling variance for use in meta-analysis. Res Synth Methods. 2017;8(2):161–180. doi:10.1002/jrsm.1218 27631635
23 Nieuwsma JA, Brancu M, Wortmann J, Smigelsky MA, King HA, Meador KG. Screening for moral injury and comparatively evaluating moral injury measures in relation to mental illness symptomatology and diagnosis. Clin Psychol Psychother. 2021;28(1):239–250. doi:10.1002/cpp.2503 32830386
24 Parr NJ, Schweer-Collins ML, Darlington TM, Tanner-Smith EE. Meta-analytic approaches for examining complexity and heterogeneity in studies of adolescent development. J Adolesc. 2019;77:168–178. doi:10.1016/j.adolescence.2019.10.009 31739275
25 Viechtbauer W. metafor: Meta-analysis package for R. Published online 2023.
26 Berkman ND, Lohr KN, Ansari M, Grading the Strength of a Body of Evidence When Assessing Health Care Interventions for the Effective Health Care Program of the Agency for Healthcare Research and Quality: An Update. In: Methods Guide for Effectiveness and Comparative Effectiveness Reviews. AHRQ Methods for Effective Health Care. Agency for Healthcare Research and Quality (US); 2008. Accessed August 8, 2023. http://www.ncbi.nlm.nih.gov/books/NBK174881/
27 Held P, Klassen BJ, Steigerwald VL, Do morally injurious experiences and index events negatively impact intensive PTSD treatment outcomes among combat veterans?. Eur J Psychotraumatology. 2021;12(1):1877026. doi:10.1080/20008198.2021.1877026
28 LoSavio ST, Hale W, Straud CL, Impact of morally injurious traumatic event exposure on cognitive processing therapy outcomes among Veterans and service members. J Mil Veteran Fam Health. 2023;9(2):40–51. doi:10.3138/jmvfh-2022-0048
29 Evans WR, Russell LH, Hall-Clark BN, Moral injury and moral healing in prolonged exposure for combat-related PTSD: A case study. Cogn Behav Pract. 2021;28(2):210–223. doi:10.1016/j.cbpra.2020.12.006
30 Paul LA, Gros DF, Strachan M, Worsham G, Foa EB, Acierno R. Prolonged Exposure for Guilt and Shame in a Veteran of Operation Iraqi Freedom. Am J Psychother. 2014;68(3):277–286.25505798
31 Litz BT, Rusowicz-Orazem L, Doros G, Adaptive disclosure, a combat-specific PTSD treatment, versus cognitive-processing therapy, in deployed marines and sailors: A randomized controlled non-inferiority trial. Psychiatry Res. 2021;297:113761. doi:10.1016/j.psychres.2021.113761 33540206
32 Norman SB, Capone C, Panza KE, A clinical trial comparing trauma-informed guilt reduction therapy (TrIGR), a brief intervention for trauma-related guilt, to supportive care therapy. Depress Anxiety. 2022;39(4):262–273. doi:10.1002/da.23244 35075738
33 Maguen S, Burkman K, Madden E, Impact of Killing in War: A Randomized, Controlled Pilot Trial. J Clin Psychol. 2017;73(9):997–1012. doi:10.1002/jclp.22471 28294318
34 McGuire AP, Howard BAN, Erickson TM, Creech SK. Moral Elevation Online Intervention for Veterans Experiencing Distress Related to Posttraumatic Stress Disorder and Moral Injury (MOVED): Pilot Trial of a 4-Week Positive Psychology Web-Based Intervention. JMIR Form Res. 2023;7(101726394):e39894. doi:10.2196/39894 36961494
35 Diekmann C, Issels L, Alliger-Horn C, Traumatized German soldiers with moral injury value-based cognitive-behavioral group therapy to treat war-related shame. Front Psychiatry. 2023;14(101545006):1173466. doi:10.3389/fpsyt.2023.1173466 37533887
36 Farrell D, Moran J, Zat Z, Group early intervention eye movement desensitization and reprocessing therapy as a video-conference psychotherapy with frontline/emergency workers in response to the COVID-19 pandemic in the treatment of post-traumatic stress disorder and moral injury-An. Front Psychol. 2023;14(101550902):1129912. doi:10.3389/fpsyg.2023.1129912 37063579
37 Smith-MacDonald L, Lusk J, Lee-Baggley D, Companions in the Abyss: A Feasibility and Acceptability Study of an Online Therapy Group for Healthcare Providers Working During the COVID-19 Pandemic. Front Psychiatry. 2021;12(101545006):801680. doi:10.3389/fpsyt.2021.801680 35115972
38 Gray MJ, Schorr Y, Nash W, Adaptive disclosure: an open trial of a novel exposure-based intervention for service members with combat-related psychological stress injuries. Behav Ther. 2012;43(2):407–415. doi:10.1016/j.beth.2011.09.001 22440075
39 Norman SB, Wilkins KC, Myers US, Allard CB. Trauma Informed Guilt Reduction Therapy With Combat Veterans. Cogn Behav Pract. 2014;21(1):78–88. doi:10.1016/j.cbpra.2013.08.001 25404850
40 Harris JI, Usset T, Voecks C, Thuras P, Currier J, Erbes C. Spiritually integrated care for PTSD: A randomized controlled trial of “Building Spiritual Strength.” Psychiatry Res. 2018;267:420–428. doi:10.1016/j.psychres.2018.06.045 29980120
41 Harris JI, Erbes CR, Engdahl BE, The effectiveness of a trauma focused spiritually integrated intervention for veterans exposed to trauma. J Clin Psychol. 2011;67(4):425–438. doi:10.1002/jclp.20777 21294116
42 Borges LM. A service member’s experience of Acceptance and Commitment Therapy for Moral Injury (ACT-MI) via telehealth: “Learning to accept my pain and injury by reconnecting with my values and starting to live a meaningful life”. J Context Behav Sci. 2019;13:134–140. doi:10.1016/j.jcbs.2019.08.002
43 Smith-MacDonald L, Jones C, Brown MRG, Moving Forward from Moral Injury: A Mixed Methods Study Investigating the Use of 3MDR for Treatment-Resistant PTSD. Int J Environ Res Public Health. 2023;20(7). doi:10.3390/ijerph20075415
44 Antal CJ, Yeomans PD, East R, Transforming veteran identity through community engagement: A chaplain-psychologist collaboration to address moral injury. J Humanist Psychol. 2023;63(6):801–826. doi:10.1177/0022167819844071
45 Cenkner DP, Yeomans PD, Antal CJ, Scott JC. A Pilot Study of a Moral Injury Group Intervention Co-Facilitated by a Chaplain and Psychologist. J Trauma Stress. 2021;34(2):367–374. doi:10.1002/jts.22642 33373486
46 Pernicano PU, Wortmann J, Haynes K. Acceptance and forgiveness therapy for veterans with moral injury: spiritual and psychological collaboration in group treatment. J Health Care Chaplain. 2022;28(sup1):S57–S78. doi:10.1080/08854726.2022.2032982 35135436
47 Smigelsky MA, Malott J, Parker R, Check C, Rappaport B, Ward S. Let’s Get “REAL”: A Collaborative Group Therapy for Moral Injury. J Health Care Chaplain. 2022;28(sup1):S42–S56. doi:10.1080/08854726.2022.2032978 35112999
48 Artra iishana P. A civilian’s artistic intuitive inquiry into loss with eight combat veterans: Thematic analysis of meaning reconstruction for grief and moral injury. Diss Abstr Int Sect B Sci Eng. 2014;74(8-B(E)):No-Specified.
49 Balmer BR, Sippola J, Beehler S. Processes and outcomes of a communalization of trauma approach: Vets & Friends community-based support groups. J Community Psychol. 2021;49(7):2764–2780. doi:10.1002/jcop.22516 33506966
50 Currier JM, McDermott RC, Fernandez P, Examining the outcomes and acceptability of a peer-led spiritual intervention for moral injury in a veteran service organization. Psychol Serv. 2023;(101214316). doi:10.1037/ser0000762
51 Ames D, Erickson Z, Geise C, Treatment of Moral Injury in U.S. Veterans with PTSD Using a Structured Chaplain Intervention. J Relig Health. 2021;60(5):3052–3060. doi:10.1007/s10943-021-01312-8 34148181
52 McGuire AP, Erickson TM, Nabulsi E. Assessing interpersonal impact of veterans with posttraumatic stress disorder and moral injury: A case study of how significant others perceive veterans undergoing a positive psychology intervention. J Psychother Integr. 2023;34(1):88–101. doi:10.1037/int0000317
53 Pyne JM, Sullivan S, Abraham TH, Rabalais A, Jaques M, Griffin B. Mental Health Clinician Community Clergy Collaboration to Address Moral Injury Symptoms: A Feasibility Study. J Relig Health. 2021;60(5):3034–3051. doi:10.1007/s10943-021-01257-y 33864575
54 Williamson V, Murphy D, Bonson A, Aldridge V, Serfioti D, Greenberg N. Restore and Rebuild (R&R) - a feasibility pilot study of a co-designed intervention for moral injury-related mental health difficulties. Eur J Psychotraumatology. 2023;14(2):2256204. doi:10.1080/20008066.2023.2256204
55 de la Rie SM, van Sint Fiet A, Bos JBA, Mooren N, Smid G, Gersons BPR. Brief Eclectic Psychotherapy for Moral Trauma (BEP-MT): treatment protocol description and a case study. Eur J Psychotraumatology. 2021;12(1):1929026. doi:10.1080/20008198.2021.1929026
56 O’Garo KGN, Koenig HG. Spiritually Integrated Cognitive Processing Therapy for Moral Injury in the Setting of PTSD: Initial Evidence of Therapeutic Efficacy. J Nerv Ment Dis. 2023;211(9):656–663. doi:10.1097/NMD.0000000000001686 37381149
57 van Minnen A, Ter Heide FJJ, Koolstra T, de Jongh A, Karaoglu S, Gevers T. Initial development of perpetrator confrontation using deepfake technology in victims with sexual violence-related PTSD and moral injury. Front Psychiatry. 2022;13(101545006):882957. doi:10.3389/fpsyt.2022.882957 36061287
58 Cameron AY, Eaton E, Brake CA, Capone C. Moral injury as a unique predictor of suicidal ideation in a veteran sample with a substance use disorder. Psychol Trauma Theory Res Pract Policy. 2021;13(8):856–860. doi:10.1037/tra0000988
59 Kelley ML, Bravo AJ, Jinkerson JD, Ogle AD, Reichwald R, Rutland JB. Remote exposure to traumatic events and PTSD symptoms among U.S. Air Force intelligence personnel: Moderating effects of morally injurious experiences. Psychol Trauma Theory Res Pract Policy. 2021;13(4):412–416. doi:10.1037/tra0000681
60 Ogle AD, Reichwald R, Rutland JB. Psychological impact of remote combat/graphic media exposure among US Air Force intelligence personnel. Mil Psychol. 2018;30(6):476–486. doi:10.1080/08995605.2018.1502999
61 Keenan MJ, Lamb T, Slattery M, Williams L, McMurtry M, Shakes D. Measuring moral injury and treatment response in justice-involved veterans: Development and validation of a new Moral Injury Scale. Traumatology. 2023;30(4):530–537. doi:10.1037/trm0000462
62 Bravo AJ, Kelley ML, Mason R, Ehlke S, Vinci C, Redman Ret LJC. Rumination as a Mediator of the Associations Between Moral Injury and Mental Health Problems in Combat-Wounded Veterans. Traumatology. 2020;26(1):52–60. doi:10.1037/trm0000198 32863781
63 Held P, Klassen BJ, Zou DS, Negative Posttrauma Cognitions Mediate the Association Between Morally Injurious Events and Trauma-Related Psychopathology in Treatment-Seeking Veterans. J Trauma Stress. 2017;30(6):698–703. doi:10.1002/jts.22234 29140560
64 Koenig HG, Youssef NA, Ames D, Teng EJ, Hill TD. Examining the Overlap Between Moral Injury and PTSD in US Veterans and Active Duty Military. J Nerv Ment Dis. 2020;208(1):7–12. doi:10.1097/NMD.0000000000001077 31738222
65 Stein NR, Mills MA, Arditte K, A scheme for categorizing traumatic military events. Behav Modif. 2012;36(6):787–807. doi:10.1177/0145445512446945 22679239
66 Youssef NA, Boswell E, Fiedler S, Moral injury, posttraumatic stress disorder, and religious involvement among U.S. veterans. Ann Clin Psychiatry Off J Am Acad Clin Psychiatr. 2018;30(2):113–121.
67 Tripp JC, McDevitt-Murphy ME, Henschel AV. Firing a weapon and killing in combat are associated with suicidal ideation in OEF/OIF veterans. Psychol Trauma Theory Res Pract Policy. 2016;8(5):626–633. doi:10.1037/tra0000085
68 Kinney AR, Gerber HR, Hostetter TA, Brenner LA, Forster JE, Stephenson RO. Morally injurious combat events as an indirect risk factor for postconcussive symptoms among veterans: The mediating role of posttraumatic stress. Psychol Trauma Theory Res Pract Policy. 2023;15(1):144–152. doi:10.1037/tra0001213
69 LaFrance WC, Vo P, Baird G, East R, Stein NR. Moral injury in Veterans with nonepileptic seizures. Epilepsy Behav. 2019;102:106681. doi:10.1016/j.yebeh.2019.106681 31766005
70 Currier JM, Farnsworth JK, Drescher KD, McDermott RC, Sims BM, Albright DL. Development and evaluation of the Expressions of Moral Injury Scale-Military Version. Clin Psychol Psychother. 2018;25(3):474–488. doi:10.1002/cpp.2170 29282787
71 Evans WR, Stanley MA, Barrera TL, Exline JJ, Pargament KI, Teng EJ. Morally injurious events and psychological distress among veterans: Examining the mediating role of religious and spiritual struggles. Psychol Trauma Theory Res Pract Policy. 2018;10(3):360–367. doi:10.1037/tra0000347
72 Litz BT, Contractor AA, Rhodes C, Distinct Trauma Types in Military Service Members Seeking Treatment for Posttraumatic Stress Disorder. J Trauma Stress. 2018;31(2):286–295. doi:10.1002/jts.22276 29669185
73 Kelley ML, Chae JW, Bravo AJ, Own soul’s warning: Moral injury, suicidal ideation, and meaning in life. Psychol Trauma Theory Res Pract Policy. 2021;13(7):740–748. doi:10.1037/tra0001047
74 Shapiro MO, Houtsma C, Schafer KM, True G, Miller L, Anestis M. Moral injury and suicidal ideation among female national guard members: Indirect effects of perceived burdensomeness and thwarted belongingness. Traumatology. 2022;30(2):231–237. doi:10.1037/trm0000424
75 Hamrick HC, Ehlke SJ, Davies RL, Higgins JM, Naylor J, Kelley ML. Moral Injury as a Mediator of the Associations Between Sexual Harassment and Mental Health Symptoms and Substance Use Among Women Veterans. J Interpers Violence. 2022;37(11–12):NP10007–NP10035. doi:10.1177/0886260520985485 33435809
76 Nillni YI, Shayani DR, Finley E, Copeland LA, Perkins DF, Vogt DS. The Impact of Posttraumatic Stress Disorder and Moral Injury on Women Veterans’ Perinatal Outcomes Following Separation From Military Service. J Trauma Stress. 2020;33(3):248–256. doi:10.1002/jts.22509 32291816
77 Koenig HG, Ames D, Youssef NA, The Moral Injury Symptom Scale-Military Version. J Relig Health. 2018;57(1):249–265. doi:10.1007/s10943-017-0531-9 29196962
78 Ames D, Erickson Z, Youssef NA, Moral Injury, Religiosity, and Suicide Risk in U.S. Veterans and Active Duty Military with PTSD Symptoms. Mil Med. 2018;184(3–4):e271–e278. doi:10.1093/milmed/usy148
79 Koenig HG, Youssef NA, Ames D, Moral Injury and Religiosity in US Veterans With Posttraumatic Stress Disorder Symptoms. J Nerv Ment Dis. 2018;206(5):325–331. doi:10.1097/NMD.0000000000000798 29494381
80 Currier JM, Holland JM, Malott J. Moral injury, meaning making, and mental health in returning veterans. J Clin Psychol. 2015;71(3):229–240. doi:10.1002/jclp.22134 25331653
81 Kelley ML, Braitman AL, White TD, Ehlke SJ. Sex differences in mental health symptoms and substance use and their association with moral injury in veterans. Psychol Trauma Theory Res Pract Policy. 2019;11(3):337–344. doi:10.1037/tra0000407
82 Hamrick HC, Kelley ML, Bravo AJ. Morally Injurious Events, Moral Injury, and Suicidality among Recent-Era Veterans: The Moderating Effects of Rumination and Mindfulness. Mil Behav Health. 2020;8(1):109–120. doi:10.1080/21635781.2019.1669509
83 Braitman AL, Battles AR, Kelley ML, Psychometric Properties of a Modified Moral Injury Questionnaire in a Military Population. Traumatology. 2018;24(4):301–312. doi:10.1037/trm0000158 30546271
84 Norman SB, Nichter B, Maguen S, Na PJ, Schnurr PP, Pietrzak RH. Moral injury among U.S. combat veterans with and without PTSD and depression. J Psychiatr Res. 2022;154(jtj, 0376331):190–197. doi:10.1016/j.jpsychires.2022.07.033 35947898
85 Maguen S, Griffin BJ, Copeland LA, Perkins DF, Finley EP, Vogt D. Gender differences in prevalence and outcomes of exposure to potentially morally injurious events among post-9/11 veterans. J Psychiatr Res. 2020;130(jtj, 0376331):97–103. doi:10.1016/j.jpsychires.2020.06.020 32805522
86 Maguen S, Griffin BJ, Copeland LA, Trajectories of functioning in a population-based sample of veterans: contributions of moral injury, PTSD, and depression. Psychol Med. 2022;52(12):2332–2341. doi:10.1017/S0033291720004249 33234177
87 Chesnut RP, Richardson CB, Morgan NR, Moral Injury and Social Well-Being: A Growth Curve Analysis. J Trauma Stress. 2020;33(4):587–597. doi:10.1002/jts.22567 32662166
88 Maguen S, Griffin BJ, Vogt D, Moral injury and peri- and post-military suicide attempts among post-9/11 veterans. Psychol Med. 2023;53(7):3200–3209. doi:10.1017/S0033291721005274 35034682
89 Maguen S, Nichter B, Norman SB, Pietrzak RH. Moral injury and substance use disorders among US combat veterans: results from the 2019–2020 National Health and Resilience in Veterans Study. Psychol Med. 2023;53(4):1364–1370. doi:10.1017/S0033291721002919 34409932
90 Nichter B, Norman SB, Maguen S, Pietrzak RH. Moral injury and suicidal behavior among US combat veterans: Results from the 2019–2020 National Health and Resilience in Veterans Study. Depress Anxiety. 2021;38(6):606–614. doi:10.1002/da.23145 33666315
91 Parry KJ, Hicken BL, Chen W, Leng J, Allen S, Burningham Z. Impact of moral injury and posttraumatic stress disorder on health care utilization and suicidality in rural and urban veterans. J Trauma Stress. 2023;36(1):117–128. doi:10.1002/jts.22889 36330588
92 Frankfurt SB, Frazier P, Engdahl B. Indirect Relations Between Transgressive Acts and General Combat Exposure and Moral Injury. Mil Med. 2017;182(11):e1950–e1956. doi:10.7205/MILMED-D-17-00062 29087864
93 Williams CL, Berenbaum H. Acts of omission, altered worldviews, and psychological problems among military veterans. Psychol Trauma Theory Res Pract Policy. 2019;11(4):391–395. doi:10.1037/tra0000394
94 Currier JM, Holland JM, Drescher K, Foy D. Initial psychometric evaluation of the Moral Injury Questionnaire--Military version. Clin Psychol Psychother. 2015;22(1):54–63. doi:10.1002/cpp.1866 24022873
95 Presseau C, Litz BT, Kline NK, An epidemiological evaluation of trauma types in a cohort of deployed service members. Psychol Trauma Theory Res Pract Policy. 2019;11(8):877–885. doi:10.1037/tra0000465
96 Bhalla A, Allen E, Renshaw K, Kenny J, Litz B. Emotional numbing symptoms partially mediate the association between exposure to potentially morally injurious experiences and sexual anxiety for male service members. J Trauma Dissociation Off J Int Soc Study Dissociation ISSD. 2018;19(4):417–430. doi:10.1080/15299732.2018.1451976
97 Battles AR, Kelley ML, Jinkerson JD, C Hamrick H, F Hollis B. Associations Among Exposure to Potentially Morally Injurious Experiences, Spiritual Injury, and Alcohol Use Among Combat Veterans. J Trauma Stress. 2019;32(3):405–413. doi:10.1002/jts.22404 31169954
98 Forkus SR, Breines JG, Weiss NH. Morally injurious experiences and mental health: The moderating role of self-compassion. Psychol Trauma Theory Res Pract Policy. 2019;11(6):630–638. doi:10.1037/tra0000446
99 Thomas ED, Weiss NH, Forkus SR, Contractor AA. Examining the Interaction Between Potentially Morally Injurious Events and Religiosity in Relation to Alcohol Misuse Among Military Veterans. J Trauma Stress. 2022;35(1):314–320. doi:10.1002/jts.22682 33964030
100 Boscarino JA, Adams RE, Wingate TJ, Impact and Risk of Moral Injury Among Deployed Veterans: Implications for Veterans and Mental Health. Front Psychiatry. 2022;13(101545006):899084. doi:10.3389/fpsyt.2022.899084 35733800
101 Lancaster SL, Irene Harris J. Measures of morally injurious experiences: A quantitative comparison. Psychiatry Res. 2018;264(qc4, 7911385):15–19. doi:10.1016/j.psychres.2018.03.057 29626826
102 Koenig HG, Ames D, Youssef NA, Screening for Moral Injury: The Moral Injury Symptom Scale - Military Version Short Form. Mil Med. 2018;183(11–12):e659–e665. doi:10.1093/milmed/usy017 29590380
103 McDaniel JT, Redner R, Jayawardene W, Moral Injury is a Risk Factor for Substance Use and Suicidality Among US Military Veterans with and without Traumatic Brain Injury. J Relig Health. 2023;62(6):3926–3941. doi:10.1007/s10943-023-01905-5 37679519
104 Fernandez PE, Currier JM. Exploring the role of moral injury outcomes in intimate relationship functioning among U.S. combat veterans. Psychol Trauma Theory Res Pract Policy. 2023;(101495376). doi:10.1037/tra0001553
105 Farnsworth JK, Drescher KD, Evans W, Walser RD. A functional approach to understanding and treating military-related moral injury. J Context Behav Sci. 2017;6(4):391–397. doi:10.1016/j.jcbs.2017.07.003
106 Jinkerson JD. Defining and assessing moral injury: A syndrome perspective. Traumatology. 2016;22(2):122–130. doi:10.1037/trm0000069
107 Jamieson N, Carey LB, Jamieson A, Maple M. Examining the Association Between Moral Injury and Suicidal Behavior in Military Populations: A Systematic Review. J Relig Health. 2023;62(6):3904–3925. doi:10.1007/s10943-023-01885-6 37592186