# ACKNOWLEDGMENTS

The authors are grateful to Payten Higgins for data abstraction efforts and editorial and citation management support, Johanna Anderson, MPH, for assistance with quality assessment, external peer reviewers, and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Jason Nieuwsma, PhD
  Associate Director, VA Integrative Mental Health
  VA Mid-Atlantic MIRECC
- Keith Meador, MD, ThM, MPH
  Director, VA Integrative Mental Health
  VA Mid-Atlantic MIRECC
- Melissa Smigelsky, PhD
  Psychologist, VA Integrative Mental Health
  VA Mid-Atlantic MIRECC