# DISCUSSION

This report was requested by the VA Integrative Mental Health (IMH) initiative, supported by the VHA Office of Mental Health and Suicide Prevention (OMHSP), to characterize published literature on moral injury broadly across populations and to synthesize available evidence on the relationship between PMIEs and MI and mental health outcomes among US Veterans and military service members. IMH’s Understanding Moral Injury project is working to address Section 506a of the STRONG Veterans Act (H.R. 6411), which directs VA to conduct research on how moral injury relates to the mental health needs of post-9/11 Veterans to inform treatment best practices.

We found that about half of studies on PMIEs or MI published to date have been conducted in the US and about half of all studies have been conducted among Veterans or military service members. Nearly 60% of US studies that reported participants’ service era were conducted exclusively among recent era (ie, post-9/11 or OIF/OEF/OND) Veterans or military service members. The pace of new research on MI among military service members has been accelerating in recent years, and the concept of MI is also expanding to non-military research. In particular, the number of studies focused on MI among health care workers has increased every year since the onset of the COVID-19 pandemic.

Characteristics of the current literature reflect that MI is still an evolving construct. Most studies to date have examined associations between PMIEs or MI and other variables, such as mental health symptoms, or described the development or validation of a PMIE/MI measure. Fewer studies have reported on development or evaluation of MI-specific interventions, and few studies have evaluated the efficacy of MI-specific interventions in RCTs.

Studies reporting associations between mental health symptoms and PMIEs or MI in US Veterans or military service members have most often examined PTSD, followed by depression, suicidal thoughts and behaviors, substance use, anxiety, and psychosocial functioning. We found low-strength evidence that PMIE exposures and MI symptoms may be correlated with increases in STBs, with the magnitude of this association being small on average. Studies with suicide-related outcomes had methodological limitations, some inconsistency across results, and imprecision in the range of effects. The relationship between MI and STBs may vary based on exposure type and other factors (eg, gender, active military status, and the specific outcome being assessed). For example, in 1 study,^88^ men who reported perpetration were 50% more likely to attempt suicide during their military service and twice as likely to attempt suicide after separation compared to those who denied perpetration, whereas women who endorsed betrayal appeared to have a higher likelihood of attempting suicide during service relative to those who denied betrayal. Another study^90^ found a weak association between MI and STBs, but reported that perceived transgressions by self or others and betrayal were more strongly associated with STBs. Based on the scope of this review and the available literature, we were unable to examine these various relationships. Future research may be indicated to explore how MI subtypes may interact with other factors to increase suicide risk.

For PTSD, depression, and anxiety, we found moderate-strength evidence that MI symptoms are correlated with greater symptom severity, and low-strength evidence of this correlation for PMIE exposures. We found low-strength evidence of positive correlations between MI symptoms and PMIE exposures for substance use outcomes, for which the evidence base is smaller, less consistent, and less precise. We also found low-strength evidence of a negative correlation between PMIE exposures or MI symptoms and relationship functioning and social engagement.

Pooled correlations were generally larger and more consistent between MI symptoms and mental health outcomes compared to correlations between PMIE exposures and these outcomes. This trend suggests a closer relationship between MI outcomes and mental health symptoms compared to PMIE exposure and mental health symptoms. Importantly, these findings do not provide insight into the causal nature of the relationship between MI and mental health symptoms. Whether MI symptoms precede, follow, or co-occur with mental health symptoms remains unclear.

Our finding of a larger positive correlation between MI symptoms and PTSD symptoms relative to other mental health outcomes, such as depression and anxiety, is consistent with prior work describing MI and PTSD as highly related yet distinct constructs. Despite similar etiologies and overlapping symptoms, a core feature of MI is its postulated distinction from PTSD.^1,105,106^ Several theoretical studies have sought to better understand the relationship between MI-related constructs and PTSD. One suggested distinction between MI and PTSD is the trauma requirement for PTSD which may not encompass the full range of morally injurious stressors that could engender MI symptoms.^21,23^ For example, perpetrating acts that are contradictory to moral codes and experiencing leadership betrayal may not always meet the trauma requirement for PTSD.^4,84^ Litz et al^72^ coded and evaluated different trauma types among service members seeking PTSD treatment. Based on their coding schema, Veterans endorsing PMIE-related traumas demonstrated differential associations with outcomes relative to those who endorsed traditional fear-based traumas. In another study,^20^ Bryan et al concluded that MI and PTSD may represent distinct constructs based on the results of an exploratory structural equation model. MI was characterized more strongly by guilt, shame, anhedonia, anger, and social alienation, whereas PTSD was characterized by increased re-experiencing (flashbacks, nightmares), hyperarousal, memory loss, and sleep difficulties.

The present review is unique in its focus on US Veterans and military service members, but our overall findings are consistent with prior systematic reviews of the associations between PMIEs/MI and mental health outcomes not limited to the US or military populations. A 2021 systematic review and meta-analysis by McEwen et al^18^ that included 59 studies conducted in military and non-military populations (police officers, teachers, journalists, refugees and asylum seekers) in the US and elsewhere also found significant associations between MI and PTSD, depression, anxiety, substance use, and suicidality outcomes. This review also found larger associations in studies of MI severity compared with studies that used combined measures of MI/PMIE exposure, which is consistent with our finding of larger positive correlations for MI symptoms and mental health outcomes compared with PMIEs. In addition, a 2023 systematic review by Jamieson et al^107^ found that exposure to morally injurious events is associated with suicide risk among military personnel and Veterans from the US and other countries and regions with similar military operational frameworks.

Limitations

The current PMIE/MI literature base has several important limitations. First, nearly all identified studies provide cross-sectional data, which can characterize associations between PMIEs/MI and other variables but cannot be used to determine the causal nature of these relationships. Further, PMIE and MI measures utilized by the included studies have faced criticism for inadequate examination of validity and for failing to index MI outcomes to PMIE exposures. Newer measures have been developed in recent years to overcome these measurement issues but have not been utilized by published studies meeting criteria for KQ2 as of the search date for this review. Examining the validity of the included measures was beyond the scope of this review. Other important limitations worth noting are risks of bias across studies arising from sampling methods, inadequate adjustment for potential confounders, and the extent and handling of missing data.

Limitations of our review methods include use of sequential rather than dual independent review for some steps including data abstraction and quality assessment. In addition, it is possible that some studies we included have overlapping samples, given that much of the research regarding PMIE/MI among US military service members and Veterans has been conducted by the same groups of core researchers or derived from shared sources of data. Wherever overlap was identified, we accounted for non-independence of observations statistically or by using data from only 1 sample (usually the largest), but due to unclear study reporting, there may be some overlap remaining among certain participant samples.

## FUTURE RESEARCH

Future research should be aimed at addressing gaps in the current evidence. As noted by several existing reviews, there is a lack of consensus on the conceptual definition of MI, and subsequently, how these constructs can be measured. Efforts to develop a shared definition of these constructs is essential to help advance this body of research. Developing and employing tools with adequate reliability and validity that can differentiate between PMIE exposures and MI symptoms is needed. The MIOS has been proposed as a tool that can potentially index PMIE exposures and assess MI symptoms. As the majority of the research is cross-sectional, future research should aim to capture longitudinal data to advance the conceptual model of MI and how exposure to PMIE causally relates to the development of MI and mental health symptoms. Relatedly, future research should also aim to identify factors that mediate and moderate the relationships between PMIE, MI, and other mental health outcomes, and to further evaluate the differential effects of PMIE and MI subtypes. Although there was only a small correlation between MI and STBs, some existing studies suggest that specific subtypes of PMIE/MI may have more profound influence on these risk factors. Building upon this research, future studies can then investigate interventions to address the psychological sequalae of MI using MI-specific measures as primary outcomes. Clearer reporting on the origins of study data and on missing data (especially missingness on PMIE or MI measures), as well as use of modern methods to impute missing data and account for plausible confounders, would reduce risk of bias concerns and help to facilitate future syntheses of MI evidence. In addition to further work on these foundational issues, future research could also improve understanding of PMIE/MI prevalence and sequelae among unique Veteran populations (based on service era, for example) and non-Veteran populations including health care workers.

## CONCLUSIONS

The pace of research on MI among Veterans and military service members has been accelerating since a definition and conceptual model for MI was proposed in 2009. About half of all published literature on PMIEs or MI has been conducted in the US and about half of all studies have been conducted among Veterans or military service members. The concept of MI is also increasingly being applied to non-military populations including health care workers. Characteristics of the current literature reflect that MI is still an evolving construct. Most studies to date have examined associations between PMIEs or MI and other variables, such as mental health symptoms, or described the development or validation of a PMIE/MI measure. Fewer studies have reported on development or evaluation of MI-specific interventions. Studies reporting associations between mental health symptoms and PMIEs or MI among US Veterans or military service members have most often examined PTSD, followed by depression, STBs, substance use, anxiety, and functioning.

For PTSD, depression, and anxiety, we found moderate-strength evidence that MI symptoms are correlated with greater symptom severity, and low-strength evidence of this correlation for PMIEs. We found low-strength evidence of positive correlations between MI symptoms and PMIE exposures for STBs and substance use outcomes, for which the evidence base is smaller, less consistent, and less precise. We also found low-strength evidence of a correlation between PMIE exposures and MI symptoms and poorer relationship functioning and social engagement.

Future research on the associations between PMIE exposures, MI, and adverse mental health outcomes using recently developed, improved measures to assess PMIE exposure and MI symptoms will further clarify these associations. Importantly, these findings do not provide insight into the causal nature of the relationship between MI and mental health symptoms. Future longitudinal research is needed to clarify the causal pathway between PMIE exposures, the development of MI, and adverse mental health outcomes. As PMIE and MI constructs are better understood in relation to established diagnoses such as PTSD, a focus of future research should also be developing and evaluating treatment interventions.