# RESULTS

## LITERATURE FLOW DIAGRAM

The literature flow diagram summarizes the results of the study selection process. A full list of excluded studies is provided in the Appendix.

Notes.

^a^282 primary studies in 343 publications and 29 reviews;

^b^50 primary studies in 70 publications.

## CHARACTERISTICS OF PUBLISHED MORAL INJURY LITERATURE

### Overview of Included Studies

Our search identified 871 potentially relevant articles after deduplication and title and abstract screening. Of these, 282 primary studies (in 343 publications) and 29 reviews met eligibility criteria (see Appendix for a list of identified review articles). Characteristics of included primary studies are shown in Table 2. About 50 percent of studies (k = 135) were conducted among Veterans or military service members. The remaining studies were conducted among health care workers (HCWs; k = 75), police or public safety personnel (k = 10), or other populations (k = 63) such as social workers, journalists, and refugees. Of the studies conducted among Veterans or military service members, many (k = 57, 42%) did not report the service era of the participants. Of those that did, 45 (58%) were conducted exclusively among recent era (ie, post-9/11, or Operation Iraqi Freedom/Operation Enduring Freedom/Operation New Dawn [OIF/OEF/OND]) Veterans/military service members, 32 (41%) were conducted among Veterans/military service members from multiple war eras, and a single study was conducted among Vietnam Veterans only. The median sample size of included studies was 175 (range: 1–52,692).

About 80% of studies were cross-sectional. Other study types included cohort or pre-post studies (k = 34), clinical trials (k = 7), laboratory studies (k = 10), and case reports or case series (k = 7). Most studies (k = 192) were quantitative, but a substantial number were qualitative (k = 51) or had a combination of quantitative and qualitative data (k = 38). Most studies (59%, k = 167) examined associations between MI or PMIEs and other variables, such as demographic factors, mental health, combat exposure, quality of life, social support, adverse childhood experiences, and physiological variables, among others. Fifty-eight studies reported on prevalence; however, most of these studies reported the prevalence of PMIE exposure types among the study sample and did not estimate prevalence of PMIE exposure or MI amongst a population. Thirty studies described the development or validation of a PMIE/MI measure and 29 evaluated the efficacy of an intervention.

Most studies (k = 104) utilized the MIES, the first published MI measure, to assess PMIE exposure/distress stemming from PMIE exposure (Figure 2). Versions of the EMIS and Moral Injury Questionnaire (MIQ) measures were used to assess MI symptoms and PMIE exposure, respectively, primarily in Veteran/military service member samples. Studies conducted among HCWs primarily utilized the MIES or MISS. The MIOS, published in 2022, was utilized in 14 studies, only 3 of which were conducted among Veterans/military service members. We identified a single study validating the Moral Injury and Distress Scale (MIDS). Other measures were utilized primarily by studies conducted among participants in the “Other” category. A substantial number of studies (k = 80) did not use a measure to assess MI/PMIEs.

Just over half (54%, k = 151) of studies were conducted in the US. Of the remaining studies, 19% were conducted in the UK or Europe (k = 54), 9% in Canada (k = 25), 5% in Australia (k = 13), and 4% in Israel (k = 10). The remaining 10% of studies were conducted in China (k = 5), Iran (k = 3), India (k = 2), Pakistan (k = 2), South Korea (k = 2), Honduras (k = 1), Japan (k = 1), Kenya (k = 1), Liberia (k = 1), Mexico (k = 1), Philippines (k = 1), South Africa (k = 1), Turkey (k = 1), and Vietnam (k = 1), or in multiple countries (k = 6). Most studies conducted in the US and Israel were of Veteran/military service member participants (Figure 2). Most studies conducted in countries in the “Other” category were of HCWs.

Table 2 Characteristics of Published Moral Injury Literature

| Military/Veteran (k=135) | Health Care Workers (k=75) | Police/PSP (k=10) | Other/Multiple (k=62)
Country
US | 99 | 29 | 2 | 21
Australia | 2 | — | 2 | 9
Canada | 8 | 8 | 4 | 5
Israel | 7 | 1 | — | 2
UK/Europe | 17 | 18 | 2 | 17
Other | 2 | 19 | — | 8
Sample size
< 10 | 8 | 2 | 2 | 3
10–99 | 47 | 18 | 4 | 22
100–200 | 24 | 12 | — | 12
201–500 | 25 | 22 | 4 | 8
501–1,000 | 15 | 8 | — | 9
>1,000 | 15 | 13 | — | 7
Study Design
Cross-sectional | 104 | 61 | 10 | 49
Cohort/pre-post | 18 | 12 | — | 4
RCT/NRCT | 6 | 1 | — | —
Case report/series | 6 | — | — | 1
Laboratory | 1 | 1 | — | 8
MI/PMIE measure
MIES | 53 | 24 | 3 | 24
EMIS | 16 | 4 | 1 | 4
MISS | 8 | 28 | — | 3
MIOS | 3 | 9 | 1 | 1
MIQ | 14 | 1 | — | 2
Other | 9 | — | 2 | 20
None | 44 | 15 | 5 | 16
Outcomes
Prevalence | 18 | 26 | 2 | 12
Associations | 79 | 51 | 4 | 34
Measure development | 10 | 7 | 2 | 11
Intervention efficacy | 24 | 2 | — | 3

Abbreviations. EMIS=Expressions of Moral Injury Scale; MI=moral injury; MIES=Moral Injury Events Scale; MIOS=Moral Injury Outcomes Scale; MIQ=Moral Injury Questionnaire; MISS=Moral Injury Symptoms Scale; NRCT=non-randomized controlled trial; PMIE=potentially morally injurious experience; PSP=public safety personnel.

The evidence base on MI has increased substantially since the 2009 publication of the article^1^ on MI in war Veterans by Litz et al. Our search identified 2 original research studies published in 2012, and the number of studies published per year has increased steadily since then, with 85 studies published in 2023 (a 4,000% increase). Until 2016, all identified studies were conducted among Veterans or military service members (Figure 1). From 2016 to 2020, small numbers of studies were conducted among other populations, including teachers, police, social workers, parents and professionals involved in Child Protective Services, animal shelter employees, journalists, refugees and asylum seekers, HCWs, and students. Beginning in 2021, coinciding with the COVID-19 pandemic, an increasing number of studies have been conducted among HCWs. In 2021, 11 studies were published of HCWs, and this number increased to 21 in 2022 and 35 in 2023. The number of studies published of other types of non-military populations has also been increasing.

Figure 1 Moral Injury Publication Trends by Participant Population

Abbreviations. EMIS=Expressions of Moral Injury Scale; HCW=health care worker; MI=moral injury; MIES=Moral Injury Events Scale; MIOS=Moral Injury Outcomes Scale; MIQ=Moral Injury Questionnaire; MISS=Moral Injury Symptom Scale; MSM=military service members; PMIE=potentially morally injurious event; PSP=public safety personnel.

### Intervention Characteristics

Twenty-five studies, 21 of which were conducted among Veterans/military service members (8 with exclusively recent era Veterans/military service members), reported on interventions for MI. Additionally, 2 pre-post studies^27,28^ and 2 case reports^29,30^ evaluated PMIE exposure and outcomes from PTSD treatments. Of the MI intervention studies conducted among Veterans/military service members, 2 were RCTs,^31,32^ 2 were pilot RCTs,^33,34^ 1 was a non-randomized trial,^35^ and the remainder were pre-post single arm studies or case studies. Of the studies conducted among HCWs, 1 was an RCT^36^ and 1 was a pre-post single arm study.^37^ Three studies (2 pre-post studies and 1 case report) reported on interventions in other populations. Most studies were published in 2021 or later (k = 23), and most were conducted in the US (k = 22).

Studies reported on 16 different interventions for Veterans/military service members. Some interventions were intended for individuals with PTSD or combat stress injuries experiencing distress associated with PMIEs that may not be adequately addressed with established evidence-based psychotherapy for PTSD. These interventions include Adaptive Disclosure (AD),^31,38^ Impact of Killing (IOK),^33^ and Trauma-Informed Guilt Reduction Therapy (TrIGR).^32,39^ Building Spiritual Strength, an intervention for spiritual distress in individuals with PTSD, does not explicitly mention moral injury and did not meet criteria for inclusion in this review, but warrants mention as an intervention addressing a similar construct that has been evaluated in an RCT^40^ and a pilot RCT.^41^

Other interventions for MI adapted existing treatment paradigms, such as Acceptance and Commitment Therapy for Moral Injury (ACT-MI)^42^ and Multi-Modal Motion-Assisted Memory Desensitization and Reconsolidation (3MDR) for MI.^43^ One pilot RCT^34^ evaluated a novel web-based intervention for MI, Moral Elevation Online Intervention for Veterans Experiencing Distress Related to PTSD and Moral Injury (MOVED). Four were group interventions, either facilitated by a mental health professional (value-based cognitive-behavioral group therapy)^35^ or co-facilitated by chaplains and mental health professionals (Moral Injury Group,^44,45^ Acceptance and Forgiveness Therapy,^46^ and Reclaiming Experiences And Loss^47^). One intervention was a residential arts-based intervention co-facilitated by a psychologist and combat Veteran.^48^ Two interventions, a community-based support program (Vets and Friends),^49^ and a group journey to Israel (Heroes to Heroes)^50^ were led by peers.

Table 3 includes descriptions of interventions for Veterans/military service members evaluated in comparative or pre-post studies. As of our search date, only 2 interventions were evaluated in RCTs sufficiently powered to examine treatment efficacy: AD and TrIGR. Impact of Killing and MOVED were evaluated in pilot RCTs and value-based cognitive-behavioral therapy was evaluated in a non-randomized trial. Eight studies used single-arm pre-post studies and 5 of these included 20 or fewer participants. Three interventions were reported only in case studies or focus groups. These include a case report of a military service member receiving ACT-MI,^42^ a study reporting on focus groups of participants of Vets and Friends, a community-based support program,^49^ and a case report of 2 combat Veterans participating in an ongoing trial of a spiritually integrated structured MI intervention delivered by chaplains.^51^

Table 3 Moral Injury Interventions for Veterans and Military Service Members Evaluated in Comparative and Pre-Post Studies

Intervention | Duration; Delivery | Studies
Interventions Evaluated in RCTs
Adaptive Disclosure (AD); Manualized psychotherapy that was developed to treat military-related PTSD, with a focus on military culture. The treatment directly addresses moral injury (MI) using imaginary narrative to help patients uncover and articulate previously unacknowledged aspects of their trauma. The treatment incorporates CBT-related interventions along with Gestalt techniques. | 6 90-minute weekly sessions; Therapist-delivered; Individual; Face-to-face | 1 RCT conducted among service members with PTSD (N=122; comparator CPT-C);^31^ 1 pre-post study^38^ conducted among service members deployed to Iraq or Afghanistan (N=44).
Trauma-Informed Guilt Reduction Therapy (TrIGR); Brief manualized intervention designed to reduce trauma-related guilt and distress in combat Veterans. Aims to help Veterans accurately appraise their combat trauma-related guilt and reidentify and reengage in their values to aid in their recovery from posttraumatic distress. | 6 90-minute weekly sessions; Therapist-delivered; Individual; Face-to-face | 1 RCT^32^ conducted among post-9/11 combat Veterans with guilt related to a combat-related trauma (N=145; comparator Supportive Care Therapy); 1 pre-post study^39^ conducted among post-9/11 combat Veterans with guilt and distress related to a combat-related trauma (N=10).
Interventions Evaluated in Pilot RCTs
Impact of Killing; Individual CBT adjunctive treatment module that focuses on the key themes of physiology of killing responses, moral injury, self-forgiveness, spirituality, making amends, and improved functioning. | 6–8 weekly 60–90-minute sessions; Therapist-delivered; Individual; Face-to-face | 1 pilot RCT^33^ conducted among combat Veterans with PTSD who completed a trauma-focused psychotherapy and reported distress regarding killing or feeling responsible for the deaths of others in war (N=33; comparator Waitlist).
Moral Elevation Online Intervention for Veterans Experiencing Distress Related to PTSD and Moral Injury (MOVED); Web-based moral elevation intervention for Veterans with PTSD symptoms and moral injury distress. | 8 online sessions over 1 month; Self-guided; Individual; Web-based | 1 pilot RCT^34^ conducted among US Veterans with PTSD symptoms (N=48; comparator assessments only); 1 case series^52^ of post-9/11 Veterans (N=2).
Interventions Evaluated in Non-Randomized Trials
Value-based CBT; Value-based semi-standardized group therapy combining elements of CBT, ACT, spiritual care, and AD. | 20 90-minute sessions over 3 weeks; Supervised by a psychiatrist and psychotherapist Group; Face-to-face | 1 NRT^35^ conducted among German Soldiers with PTSD (N=85; comparator Waitlist).
Interventions Evaluated in Single Arm Pre-Post Studies
Acceptance and Forgiveness Therapy; Psychospiritual group intervention that guides Veterans with MI experientially from a trauma-focused to restorative view of self. | 10 weekly sessions; Co-facilitated by a chaplain and mental health provider; Group; Face-to-face | 1 pre-post study^46^ conducted among US Veterans (N=35).
Heroes to Heroes; Journey to Israel in which the group is guided through an established itinerary of sacred places, activities, and rituals aimed at restoring a sense of transcendence and belonging that may equip and empower them to “come home” upon returning to the US. | 10 days; Led by Veteran peers; Group; Face-to-face | 1 pre-post study^50^ conducted among US Veterans with a combat deployment (N=101).
Moral Injury Group; Provides educational information about MI and explores related topics. Leaders invite Veterans to share experiences from their service and guide Veterans toward integrating these concepts into their own self-understanding and narrative. Concludes with a ceremony where participants share testimonies of their MI with the public. | 12 90-minute weekly sessions; Co-facilitated by psychologist and chaplain; Group; Face-to-face | 1 pre-post study^45^ conducted among US Veterans (N=40); 1 case report^44^ of a US Veteran (N=1).
Mental Health Clinician Community Chaplain Collaboration (MC4); Builds on community clergy’s existing skills in spiritual counseling to address MI symptoms through facilitation of forgiveness and community reintegration. | Weekly or biweekly sessions over 3 months; Delivered by community clergy; Individual; Face-to-face | 1 pre-post study^53^ conducted among US Veterans in treatment for PTSD (N=13).
Multi-Modal Motion-Assisted Memory Desensitization and Reconsolidation (3MDR); Virtual-reality exposure-based trauma therapy. Participants walk on a treadmill while a clinician guides them through selection of symbolic representations and music and then viewing of images. Participants describe each image and associated PMIEs, then read numbers displayed on a virtual ball between images. | 6 weekly sessions; Clinician-guided; Individual; Face-to-face | 1 pre-post study^43^ conducted among Canadian Veterans and ADSMs with treatment-resistant PTSD who experienced trauma in a military combat setting (N=11).
Reclaiming Experiences and Loss (REAL); Interdisciplinary group therapy that emphasizes self-examination of one’s inner world and the MIE through the lens of loss. The 3 phases of the group focus on: inventorying losses, telling stories, and reclaiming lives. | 12 90-minute weekly sessions; Co-facilitated by a chaplain and mental health professional Group; Face-to-face | 1 pre-post study^47^ conducted among US Veterans (N=15).
Restore and Rebuild (R&R); Psychotherapy with key themes of processing the event, self-compassion, connecting with others and core values. Includes review of life experiences, psychoeducation, and emotional regulation. | 20 weekly sessions; Therapist-delivered; Individual; Online | 1 pre-post study^54^ conducted among UK Veterans receiving psychological treatment (N=20).
The Warrior’s Journey; Residential arts-based intervention. Engages participants in art-based reviews of their experiences with distress and renewal. On the final day, participants present a story of their current understanding of past, present, and future to an audience. | 5 days; Co-facilitated by a psychotherapist combat Veteran Group; Face-to-face | 1 pre-post study^48^ conducted among US male combat Veterans with PTSD (N=8).

Abbreviations. ACT=Acceptance and Commitment Therapy; AD=Adaptive Disclosure; ADSM=active-duty service member; CBT=cognitive behavioral therapy; CPT=cognitive processing therapy; CPT-C=cognitive processing therapy – cognitive only version; MI=moral injury; MOVED= Moral Elevation Online Intervention for Veterans Experiencing Distress Related to PTSD and Moral Injury; NRT=non-randomized trial; PMIEs=potentially morally injurious experiences; TrIGR=Trauma-Informed Guilt Reduction Therapy.

Interventions evaluated among HCWs included virtual group EMDR^36^ and an online group therapy including ACT and MI psychoeducation and experientials (Accepting Moral Pain and Suffering for Healthcare Providers [AMPS-HCP]).^37^ Interventions evaluated in other populations included Brief Eclectic Psychotherapy for Moral Trauma (BEP-MT), presented in a case report of a refugee,^55^ Spiritually Integrated Cognitive Processing Therapy (SICPT), evaluated in a pre-post study conducted with religious patients with MI and PTSD symptoms,^56^ and an intervention that utilized “deepfake” technology for perpetrator confrontation, evaluated in a pre-post study conducted with women with PTSD and MI who had experienced sexual violence.^57^

## MORAL INJURY AND MENTAL HEALTH AND FUNCTIONING OUTCOMES AMONG US VETERANS AND MILITARY SERVICE MEMBERS

### Overview of Included Studies

Of the studies included for Key Question 1, 50 studies (in 70 publications) reported quantitative results on the association between PMIE exposure and/or MI symptoms and mental health and/or functioning outcomes in US Veterans or military service members. These studies examined the association between PMIE exposure/MI symptoms and PTSD (k = 41), depression (k = 29), STBs (k = 23), substance use (k =17), anxiety (k = 13), and functioning (k = 3) including social activity, community engagement, relationship functioning, and physical functioning. Detailed study characteristics and risk of bias assessments are provided in the Appendix.

All studies were observational, and most were cross-sectional. Eleven studies were longitudinal, but in most cases association data in these studies were cross-sectional. The cross-sectional nature of most data is important to highlight, as these data do not provide insight into whether PMIE exposure or MI symptoms preceded, co-occurred with, or followed mental health symptoms or diagnosis. Participants were recruited from outpatient mental health settings in 15 studies and inpatient mental health treatment in 1 study.^58^ The remaining studies recruited participants from a variety of community sources (ie, not treatment settings) or multiple settings.

Study median sample size was 263 (range: 40–14,057). Thirty-two studies enrolled Veterans only, 10 studies were conducted among military service members only (active-duty service members and/or National Guard and Reserve members), and 8 studies included both populations. Two studies^59,60^ examined US Air Force intelligence, surveillance, and reconnaissance (ISR) personnel. One study^61^ included justice-involved Veterans participating in Veterans Treatment Court. In most studies that reported participants’ service era (28 of 31 studies, 90%), recent-era Veterans/military service members made up at least 75% of the sample. In studies that reported deployment history, most studies (27 of 35 studies, 77%) consisted entirely of Veterans/military service members with at least 1 prior deployment. Fourteen studies had specific inclusion criteria beyond Veteran/military service member status: combat wounded,^62^ PTSD diagnosis or symptoms,^27,63–66^ hazardous alcohol use or substance use,^58,67^ suicidal ideation,^58^ mild traumatic brain injury (mTBI),^68^ psychogenic non-epileptic seizures,^69^ PMIE exposure,^59^ MI symptoms,^70^ religious/spiritual struggles,^71^ and experience of a Criterion A trauma event.^72^

All but 3 studies^73–76^ included primarily male participants, and 3 studies did not report on gender. Eight studies^14,64,66,71,74,77–79^ comprised primarily Black participants, and 1 study^80^ included mainly participants of Hispanic ethnicity. The remaining studies included primarily White non-Hispanic participants, and 8 studies did not report on race or ethnicity. Of the studies that reported mean age of the study sample (k = 39), mean age was between 23 and 28 years in 5 studies, between 31 and 39 years in 18 studies, between 40 and 47 years in 7 studies, between 50 and 59 years in 7 studies, and 62 years in 2 studies.

About half of studies used the MIES (k = 28). Other measures used to assess PMIE exposure or MI symptoms included the EMIS-M (k = 7) or EMIS-M-SF (k = 1), the MIQ-M (k = 7), the MISS-M (k = 3) or MISS-M-SF (k = 2), the BMIS (k = 1), and the MIS (k = 1). No studies were identified that used the recently published MIDS or MIOS measures that met screening eligibility criteria for KQ2. Studies reported associations for total score only (k = 17), subscale(s) only (k = 13), or both (k = 13). In 9 studies, only part of the measure was used, or changes were made to the measure. Two studies^15,81–83^ used a modified version of the MIQ-M that included follow-up items for each exposure item that assessed MI symptoms associated with the exposure. One study^20^ used items from the Deployment Risk and Resilience Inventory (DRRI) and Differential Emotions Scale (DES) to assess MI symptoms of sorrow, regret, shame, and alienation. Six studies did not use a measure to assess PMIE exposure or MI symptoms. These studies looked at self-reported PMIEs, often coding traumatic events associated with PTSD symptoms as PMIEs.

Three population-based survey studies (reported in 8 publications^76,84–90^) with analyses that controlled for important potential confounders and appropriately handled missing data were rated low risk of bias. However, most studies had moderate risk of bias due to concerns related to sampling methods, inadequate controlling for potential confounders, and lack of detail on the degree and handling of missing data, including whether data were missing for PMIE or MI measures. As stated above, some studies did not use validated measures for PMIEs/MI, instead coding trauma types as PMIEs.

Pooled correlations of PMIE exposures and MI symptoms with mental health and functioning outcomes are presented in Table 4. Associations using the MIES, MIQ-M, or reporting frequency of PMIE exposures without a measure were included in the pooled analysis of PMIE exposures. Associations using the EMIS-M, MIS, MISS-M, modified MIQ-M, or items from non-MI scales that were used to assess symptoms of MI were included in the pooled analysis of MI symptoms. Associations using the BMIS were included for both analyses (see Table 1 in Methods). All pooled correlations are statistically significant (ie, p < .05) with the exception of PMIE exposures and MI symptoms with relationship functioning and social engagement. Correlations were generally larger and more consistent between MI symptoms and STBs, PTSD, depression, and anxiety compared to correlations between PMIE exposures and these outcomes.

Table 4 Pooled Correlations of PMIE Exposures and MI Symptoms with Mental Health and Functioning Outcomes

| Total N | Samples | Estimates | Pooled Correlation
Suicidal Thoughts and Behaviors
PMIE Exposures | 1933 | 10 | 16 | 0.19, 95% CI [0.05, 0.31], 95% PI [−0.23, 0.54]
MI Symptoms | 4161 | 9 | 12 | 0.27, 95% CI [0.10, 0.43], 95% PI [−0.29, 0.69]
PTSD
PMIE Exposures | 14462 | 26 | 60 | 0.36, 95% CI [0.28, 0.44], 95% PI [−0.11, 0.70]
MI Symptoms | 4210 | 13 | 15 | 0.57, 95% CI [0.46, 0.66], 95% PI [0.12, 0.83]
Depression
PMIE Exposures | 12937 | 20 | 36 | 0.29, 95% CI [0.19, 0.38], 95% PI [−0.14, 0.63]
MI Symptoms | 2319 | 8 | 9 | 0.45, 95% CI [0.23, 0.63], 95% PI [−0.25, 0.84]
Anxiety
PMIE Exposures | 4018 | 8 | 13 | 0.25, 95% CI [0.08, 0.41], 95% PI [−0.26, 0.66]
MI Symptoms | 1347 | 5 | 6 | 0.48, 95% CI [0.27, 0.65], 95% PI [−0.07, 0.81]
Substance Use
PMIE Exposures | 2281 | 7 | 15 | 0.29, 95% CI [0.08, 0.47], 95% PI [−0.31, 0.72]
MI Symptoms | 3558 | 7 | 9 | 0.18, 95% CI [0.08, 0.29], 95% PI [−0.13, 0.46]
Relationship Functioning/Social Engagement
PMIE Exposures/MI Symptoms | 7679 | 3 | 7 | −0.31, 95% CI [−0.70, 0.22], 95% PI [−0.89, 0.64]

Note. All pooled correlations are statistically significant (ie, p < .05) with the exception of Relationship Functioning/Social Engagement.

Abbreviations. PI=95% prediction interval.

## SUICIDAL THOUGHTS AND BEHAVIORS

Both PMIE exposures and MI symptoms may be positively correlated with suicidal thoughts and behaviors (STBs) based on 15 studies and 9 studies, respectively. Our confidence in these findings is low due to study methodological limitations, some inconsistency across studies, and imprecision.

### Overview of Included Studies

| PMIE and STBs | MI and STBs
Number of relevant studies; Number of participants (range) | Evaluated in 15 studies; Ns = 40–14,057 | Evaluated in 9 studies; Ns = 62–1,487
Sample sources | 7 clinical samples; 5 community samples; 3 population-based samples | 8 community samples; 1 combined clinical and community sample
Number of studies limited to post-9/11 service era Veterans or military service members | 4 studies | 1 study
Number of studies finding a positive correlation | 14 studies | 8 studies
Number of studies finding a negative correlation or non-significant association | 1 study | 1 study
Number of studies included in meta-analysis | 10 studies | 9 studies

We identified 15 studies examining associations between PMIE exposures and STBs, 10 of which (total N = 1,933) could be included in meta-analyses. PMIE exposures were significantly positively correlated with STBs, but the magnitude of this association was small on average (r_pooled_ = 0.19).

Findings from 2 large population-based studies,^88,90^ which were not included in meta-analyses, also generally found positive correlations between PMIE exposures and STBs. However, associations varied according to PMIE exposure type and other factors such as gender, active military status, and the specific suicidal thoughts and behaviors being assessed. The largest study,^88^ which included 14,057 post-9/11 Veterans participating in the Comparative Health Assessment Interview (CHAI) study, examined the relationships between specific categories of PMIE (acts of perpetration, witnessing, and betrayal), suicide attempts, and gender. This study found that men who reported exposure to perpetration were 50% more likely to attempt suicide during their military service (adjusted risk ratio [ARR] = 1.52, 95% CI [1.05, 2.18]) and twice as likely to attempt suicide after separation (ARR = 2.01, 95% CI [1.43, 2.80]) relative to those who denied perpetration. However, perpetration was not a significant predictor of suicide attempts during or after military service among women. Men who endorsed betrayal were nearly twice as likely to attempt suicide during service relative to those who reported no betrayal (ARR = 1.90, 95% CI [1.25, 2.87]) but this association was attenuated after separation from service (ARR = 1.29, 95% CI [0.89, 1.86]). Women who endorsed betrayal appeared to have a higher likelihood of attempting suicide during service relative to those who denied betrayal (ARR = 1.56, 95% CI [1.00, 2.41]), though this result was non-significant (the association was similar but significant after separation from service: ARR = 1.62, 95% CI [1.06, 2.44]). Exposure to witnessing was not a significant predictor of suicide attempts for men or women during or after military service.

A second large cross-sectional study^90^ conducted among a sample of combat Veterans (N = 1,321) participating in the 2019–2020 National Health and Resilience in Veterans Study (NHRVS) found that MIES total scores were weakly associated with lifetime suicide plans (odds ratio [OR] = 1.03, p < .01) but not current suicidal ideation or lifetime suicide attempts. When assessed by MIES subscales, perceived transgressions by self or others and betrayal were associated with current suicidal ideation, lifetime suicide plans, and lifetime suicide attempts (ORs = 1.21–1.27, p's < .05).

Results from 2 additional studies not included in the meta-analyses are also consistent with the overall finding of a positive correlation between PMIE exposure and STBs. A study of 1,545 Veterans who completed a routine PTSD intake assessment at a walk-in clinic at the Salt Lake City VA Medical Center^91^ found that a 1-unit increase in MIES score was weakly associated with an increased risk of suicidality as represented by ICD-19 diagnosis codes for suicidal ideation, attempt, or self-inflicted injury (OR = 1.02, 95% CI [1.0, 1.04]). A smaller study of 564 combat Veterans participating in the 2013 NHRVS^5^ found that MIES total score predicted significantly higher odds of current suicidal ideation (OR = 1.23, 95% CI [1.05, 1.45]), but not post-deployment suicide attempts (OR = 1.07, 95% CI [0.82, 1.40]).

Nine studies of MI symptoms (total N = 4,161) reported on STBs and could be included in meta-analyses. MI symptoms were significantly positively correlated with STBs, but just as with PMIE exposure, the magnitude of this association was small on average (r_pooled_ = 0.27). Findings across studies were mostly consistent in reporting small to moderate positive correlations.

Mediators of the association between PMIE/MI and STBs included PTSD symptoms,^15^ guilt,^92^ meaning made of a salient stressor,^80^ thwarted belongingness,^74^ perceived burdensomeness,^74^ and altered worldviews.^93^ One study reported that the interaction of MI and PTSD was a significant predictor of suicidal ideation and suicide attempts.^20^

### PTSD

PMIE exposures may be correlated with higher PTSD symptom severity based on 29 studies, and MI symptoms are likely correlated with greater PTSD symptom severity based on 13 studies. Our confidence in findings for PMIE exposure is low due to study methodological limitations, some inconsistency across studies in the direction of effect, and imprecision, while our confidence in findings for MI symptoms is moderate due to greater consistency and precision.

#### Overview of Included Studies

| PMIE and PTSD | MI and PTSD
Number of relevant studies; Number of participants (range) | Evaluated in 29 studies; Ns = 50–7,200 | Evaluated in 13 studies; Ns = 62–930
Sample sources | 17 community samples; 9 clinical samples; 2 population-based samples | 10 community samples; 1 clinical sample; 1 combined clinical and community sample
Number of studies limited to post-9/11 service era Veterans or military service members | 10 studies | 1 study
Number of studies finding a positive correlation | 25 studies | 13 studies
Number of studies finding a negative correlation or non-significant association | 4 studies | None
Number of studies included in meta-analysis | 26 studies | 13 studies

Overall, among a total of 42 studies, all but 4 found that PMIE exposure or MI symptoms were positively correlated with PTSD symptom severity (measured most frequency using the PTSD Checklist [PCL]). Twenty-six studies of PMIE exposures (total N = 14,462) and 13 studies of MI symptoms (total N = 4,210) could be included in meta-analyses. PMIE exposures and MI symptoms were significantly positively correlated with PTSD outcomes, with pooled correlations ranging from small to moderate in magnitude (r_pooled_ = 0.36–0.57). Several studies reported notably large positive correlations, particularly for the association between MI symptoms and PTSD outcomes.

Similar to findings for STBs, associations between PMIE exposure or MI symptoms and PTSD may vary according to particular PMIE types or other factors. In a study conducted among combat Veterans (N = 1,321) participating in the 2019–2020 NHRVS,^84^ PMIE exposure by perpetration and betrayal were significantly associated with current probable PTSD (OR = 2.14, 95% CI [1.26, 3.65] and OR = 3.08, 95% CI [1.86, 5.12], respectively). PMIE exposure by witnessing may have also been associated with current probable PTSD, but the result was non-significant (OR = 1.61, 95% [0.97, 2.67]). In exploring the temporal relationship between MI and PTSD at 2 time points, Currier^94^ found that self-directed MI predicted greater PTSD severity at 6 months. Conversely, PTSD Cluster D symptoms (changes in cognition and mood) predicted self-directed MI at 6 months, suggesting a complex and potentially bidirectional relationship between the 2 conditions. No temporal relationship between other-directed MI and PTSD were evident when controlling for other factors.

Mediators of the association between PMIEs and PTSD symptom severity included MI,^15^ guilt,^4,92^ shame,^4^ anger,^4^ meaning made of a salient stressor,^80^ religious/spiritual struggles,^71^ negative post-trauma cognitions,^63^ and altered worldviews.^93^ The only potential mediator of the association between MI and PTSD symptom severity was problem-focused thoughts.^62^ One study^66^ examined religious involvement as a moderator of the effect of MI on PTSD symptom severity, finding that religious involvement attenuated the effect of MI on PTSD, but only for Veterans who served in non-Middle Eastern theaters.

## DEPRESSION

PMIE exposures may be correlated with greater depression symptom severity based on 22 studies; MI symptoms are likely correlated with greater depression symptom severity based on 8 studies. Our confidence in findings for PMIE exposure is low due to study methodological limitations, some inconsistency across studies in the direction of effect, and imprecision. Our confidence in findings for MI symptoms and depression is moderate due to consistency and precision of findings.

### Overview of Included Studies

| PMIE and Depression | MI and Depression
Number of relevant studies; Number of participants (range) | Evaluated in 22 studies; Ns = 40–7,200 | Evaluated in 8 studies; Ns = 62–624
Sample sources | 12 community samples; 8 clinical samples; 2 population-based samples | 7 community samples; 1 combined clinical and community sample
Number of studies limited to post-9/11 service era Veterans or military service members | 10 studies | 1 study
Number of studies finding a positive correlation | 17 studies | 8 studies
Number of studies finding a negative correlation or non-significant association | 5 studies | 1 study
Number of studies included in meta-analysis | 20 studies | 8 studies

Overall, among a total of 30 studies, all but 6 found that PMIE exposure or MI symptoms were correlated with greater depression symptom severity (measured most frequently with the PHQ tool). Twenty studies of PMIE exposures (total N = 12,937) and 8 studies of MI symptoms (total N = 2,319) reported depression outcomes and could be included in meta-analyses. PMIE exposures and MI symptoms were significantly positively correlated with depression outcomes, with pooled correlations ranging from small to moderate in magnitude (r_pooled_ = 0.29–0.45). Nearly all studies reported positive correlations, and these were generally larger for the association between MI symptoms and depression outcomes compared with PMIE exposure.

Mediators of the association between PMIEs and depression symptom severity included PTSD symptoms,^15^ religious/spiritual struggles,^71^ meaning made of a salient stressor,^80^ negative post-trauma cognitions,^63^ and altered worldviews.^93^ The only potential mediator of the association between MI and depression symptom severity was problem-focused thoughts.^62^

## ANXIETY

PMIE exposures may be correlated with more severe anxiety symptoms based on 8 studies and MI symptoms are likely correlated with greater anxiety symptom severity based on 5 studies. Our confidence in findings for PMIE exposure is low due to study methodological limitations, some inconsistency across studies in the direction of effect, and imprecision, while our confidence in findings for MI symptoms is moderate due to greater consistency and precision.

### Overview of Included Studies

| PMIE and Anxiety | MI and Anxiety
Number of relevant studies; Number of participants (range) | Evaluated in 8 studies; Ns = 72–1,086 | Evaluated in 5 studies; Ns = 154–420
Sample sources | 6 community samples; 1 clinical sample; 1 population-based sample | 4 community samples; 1 combined clinical and community sample
Number of studies limited to post-9/11 service era Veterans or military service members | 2 studies | None
Number of studies finding a positive correlation | 6 studies | 5 studies
Number of studies finding a negative correlation or non-significant association | 2 studies | None
Number of studies included in meta-analysis | 8 studies | 5 studies

Eight studies of PMIE exposures (total N = 4,018) and 5 studies of MI symptoms (total N = 1,347) reported anxiety outcomes and could be included in meta-analyses. PMIE exposures and MI symptoms were significantly positively correlated with anxiety outcomes, with pooled correlations ranging from small to moderate in magnitude (r_pooled_ = 0.25–0.48). Correlations from studies of PMIE exposures were inconsistent in both magnitude and direction, while all studies of MI symptoms reported positive correlations.

Results from 2 of the largest studies^85,95^ suggest that the nature of the relationship between PMIE exposure and anxiety symptoms may vary by PMIE type and gender. In a population-based survey^85^ of 7,200 US service members who participated in the Veterans Metrics Initiative, both men and women who reported exposure to witnessing or betrayal had higher odds of screening positive for anxiety (witnessing: women OR = 2.33, 95% CI [1,72, 3.15] and men OR = 2.45, 95% CI [2.09, 2.88] and betrayal: women OR = 2.13, 95% CI [1.57, 2.90] and men OR = 1.68, 95% CI [1.41, 2.00]). For perpetration, only men had higher odds of screening for anxiety (OR = 1.77, 95% CI [1.47, 2.14]). Similarly, in a study of active duty military service members recruited to participating in a STRONG STAR epidemiological study^95^ that classified PTSD Criterion A events as MI involving self or others, PMIE exposure involving self was significantly associated with anxiety symptom severity but PMIE exposure involving others was not.

Mediators of the association between PMIEs and anxiety symptom severity included PTSD symptoms^15,96^ and religious/spiritual struggles.^71^ The only potential mediator of the association between MI and anxiety symptom severity was problem-focused thoughts.^62^

## SUBSTANCE USE

PMIE exposures and MI symptoms may be positively correlated with hazardous alcohol use and overall substance use based on findings from 11 and 7 studies, respectively. Our confidence in these findings is low due to study methodological limitations, inconsistency, and imprecision.

### Overview of Included Studies

| PMIE and Substance Use | MI and Substance Use
Number of relevant studies; Number of participants (range) | Evaluated in 11 studies; Ns = 50–7,200 | Evaluated in 7 studies; Ns = 154–1,487
Sample sources | 6 community samples; 3 clinical sample; 2 population-based sample | 6 community samples; 1 combined clinical and community sample
Number of studies limited to post-9/11 service era Veterans or military service members | 5 studies | None
Number of studies finding a positive correlation | 8 studies of alcohol use; 4 studies of substance use | 4 studies of alcohol use; 2 studies of substance use
Number of studies finding a negative correlation or non-significant association | 2 studies of alcohol use; 1 study of substance use | 1 study of alcohol use; 2 studies of substance use
Number of studies included in meta-analysis | 8 studies | 7 studies

Note. Some studies evaluated alcohol use and substance use separately and had divergent findings.

Eight studies of PMIE exposures (total N = 2,281) and 7 studies of MI symptoms (total N = 3,558) reported on alcohol and/or substance use and could be included in meta-analyses. PMIE exposures and MI symptoms were significantly positively correlated with substance use, but the magnitude of this association was small on average (r_pooled_ = 0.18–0.29).

Among 10 studies^23,85,89,93,95,97–101^ examining associations between PMIE exposure and alcohol use (most frequently assessed using the AUDIT tool), 8^23,85,89,97–101^ found that PMIE exposure was positively correlated with hazardous alcohol use, although this finding was only observed for men in 2 studies.^85,97^ Among 5 studies^70,81,83,102^ of MI symptoms and alcohol use, 4^70,81,83^ found that MI symptoms were positively correlated with hazardous alcohol use or misuse.

Among 5 studies^23,69,89,98,100^ of PMIE exposure and substance use (not specific to alcohol use), 4^23,89,98,100^ identified a positive correlation between PMIE exposure and substance use including a large study^100^ of 1,032 participants recruited from an outpatient clinic in Pennsylvania which found that PMIE exposure was associated with a greater odds of past year opioid dependence (OR = 2.30, p = .008) and lifetime marijuana use (OR = 2.06, p = .002). Among 4 studies^75,81,83,103^ of MI symptoms and substance use (not specific to alcohol use), 2^83,103^ found that MI symptoms were positively correlated with drug use or general substance use.

A single study examined mediators of the associations between PMIE exposure/MI symptoms and substance use outcomes, reported in 2 different publications.^15,97^ Among a community sample of 380 recent-era combat Veterans,^97^ researchers examined associations between combat exposure and alcohol use and the mediating effects of PMIE exposure and spiritual injury (such as alienation from and/or anger towards respective higher power). PMIE exposure and spiritual injury sequentially mediated the association between combat and alcohol such that more exposure to PMIEs and a higher level of spiritual injury were related to more alcohol use, R^2^ = .17. In multiple-group models, this mediation effect was only significant among men. A second analysis^15^ conducted among a subsample of 244 Veterans, active duty military service members, and reservists/National Guard members who deployed at least once for Operation Iraqi Freedom or Operation Enduring Freedom found that MI was positively correlated with hazardous alcohol use (r = 0.46) but this association was no longer significant after controlling for the effects of PMIE types (ie, atrocities of war, psychological consequences of war, and leadership failure/betrayal) and PTSD symptoms.

## FUNCTIONING

PMIE exposures and MI symptoms may be negatively correlated with relationship functioning and social engagement based on 3 studies, but our confidence in this finding is low due to the small number of studies overall, study methodological limitations, and imprecision. In meta-analysis of these 3 studies (total N = 7,679), PMIE exposure and MI symptoms appeared to be negatively correlated with relationship functioning or social engagement outcomes, but this association was non-significant and fairly small on average (r_pooled_ = −0.31). Whether PMIE exposure or MI symptoms are associated with other functioning domains (eg, work functioning, parenting) is unclear, as these associations have only been evaluated in a single study.

### Overview of Included Studies

| PMIE/MI and Functioning
Number of relevant studies; Number of participants (range) | Evaluated in 3 studies; Ns = 65–7,200
Sample sources | 1 community sample; 1 combined clinical and community sample; 1 population-based sample
Number of studies limited to post-9/11 service era Veterans or military service members | 1 study
Number of studies included in meta-analysis | 3 studies

A multi-site, cross-sectional study^77,102^ of Veterans (N = 414–425) found that MI symptoms (as measured by MISS-M and MISS-M-SF) were associated with lower measures of relationship quality, community involvement, and physical functioning. In a cross-sectional study^104^ of combat Veterans participating in a peer-led intervention that promotes spiritual healing and social connection, MI symptoms were negatively correlated with intimate relationship functioning (r = −0.49) among participants who were married or in domestic partnerships (N = 65).

Based on cross-sectional data from participants (N = 7,200) in the Veterans Metrics Initiative, a longitudinal study^85^ examining transitions to civilian life among post-9/11 Veterans, different types of PMIEs (as measured by MIES subscales) were variably associated with different functional impairments, which further varied by gender. A subsequent analysis^87^ incorporating a larger sample (N = 9,566) from the Veterans Metrics Initiative found that higher scores on MI reactions (measured by MIES) were associated with lower levels of baseline social functioning and that measures of social well-being changed differently over time depending on whether MI reactions were self- or other-focused.