# METHODS

## REGISTRATION AND REVIEW

A protocol for this review was preregistered on OSF (https://doi.org/10.17605/OSF.IO/B5794). A draft version of this report was reviewed by external peer reviewers; their comments and author responses are located in the Appendix.

## KEY QUESTIONS AND ELIGIBILITY CRITERIA

The following key questions were the focus of this review:

Key Question 1 | What are the characteristics of evidence on MI with regards to:; - The distribution of studies over time across populations; - Measures used to assess MI; - Characteristics of interventions to address MI
Key Question 2 | What is the association between PMIE and MI and suicidal thoughts and behaviors (STBs) and other mental health outcomes among Veterans and US military service members?

Study eligibility criteria are shown in the table below. Key Question (KQ) 1 corresponds to the descriptive portion of the review, and KQ2 corresponds to the systematic review (SR). For KQ1, all published research studies with a focus on individuals with exposure to PMIE or MI were included. We did not use an explicit definition of PMIEs or MI during screening. We included studies if the main topic of the research was MI or PMIE exposure, as defined by the authors, to address the first aim of describing the current state of the literature. We did not include studies on moral distress only, or studies where MI was included only as a secondary outcome (for example, qualitative studies of work experiences in HCWs where MI was one of several themes that emerged from interviews). For KQ2, studies with quantitative measurement of the association between PMIEs or MI and specified mental health outcomes in US Veterans or military service members were included.

| Eligibility Criteria
Population | KQ1: Adults with MI or who have experienced potentially morally injurious events (PMIEs); KQ2: US military service members and Veterans with MI or who have experienced PMIEs. We will include Veterans from any service era but will prioritize studies conducted among post-9/11 Veterans.
Intervention | KQ1: Exposure to moral injury or PMIEs, interventions to prevent or treat MI, use of assessment tools to identify MI; KQ2: Exposure to moral injury or PMIEs.
Comparator | Any (eg, adults without MI/PMIEs) or none.
Outcomes | KQ1: Any; KQ2: Association between MI or PMIEs and STBs and other mental health outcomes (ie, symptoms or diagnoses of PTSD, depression, anxiety, and substance use; functioning). Studies must include a quantitative measure of the association.
Study Design | KQ1: Published research studies; KQ2: Published quantitative studies with sample size ≥ 10.

## SEARCHING AND SCREENING

To identify articles relevant to the key questions, a research librarian searched MEDLINE and PsycINFO through February 2024 using terms for moral injury (see Appendix for complete search strategies). For KQ2, additional citations were identified from hand-searching reference lists of relevant systematic reviews. Screening was conducted in 2 stages. First, a single investigator screened English-language titles, abstracts, and full-text articles for studies addressing KQ1. Second, titles, abstracts, and full-text articles of studies included from the initial screening step were independently reviewed by 2 investigators for inclusion for KQ2, and disagreements were resolved by consensus.

## DATA ABSTRACTION AND RISK OF BIAS ASSESSMENT

For the descriptive part of the review (KQ1), study design, study type, and population and exposure characteristics were abstracted from all included studies. For the SR (KQ2), estimates of associations between PMIE exposures and/or MI symptoms and outcomes were also abstracted. For KQ2, we examined the data source for each publication and linked publications with overlapping samples. For KQ1, we linked publications from the same study during abstraction of study characteristics but did not systematically examine the data source for each publication. The internal validity (risk of bias) of each study included in the SR was rated using the Quality in Prognosis Studies (QUIPS) tool^21^; internal validity was not assessed for the remaining studies that were included only in the descriptive portion of the review. All data abstraction and internal validity ratings were first completed by 1 investigator and then checked by another; disagreements were resolved by consensus or discussion with a third investigator (see Appendix for risk of bias ratings).

## SYNTHESIS

Characteristics of available research on moral injury (KQ1) were described narratively and summarized using visualizations. When 3 or more sufficiently comparable studies reported associations between PMIE exposures or MI symptoms and an eligible mental health outcome in US Veterans or military service members (KQ2), study results were synthesized with meta-analysis.

Associations between PMIE exposures and/or MI symptoms and outcomes were typically reported as correlation coefficients. When only unstandardized regression coefficients were reported, coefficients and their standard errors were used to calculate t-values, which were further transformed to (partial) correlation coefficients. A small number of studies applied thresholds to a continuous PMIE exposure scale to create exposed and unexposed groups, then reported mean values of outcome measures in each group. In these cases, group means and standard deviations were used to calculate biserial correlation coefficients.^22^ All correlation coefficients were transformed with Fisher’s r-to-z transformation for analyses, then back-transformed to correlations for interpretation and reporting.

For all outcomes except for functioning (for which sufficient data were not available), the relationship between PMIE exposure and outcomes, and between MI symptoms and outcomes, was examined separately (see Table 1 for detail on how we determined which associations to include for PMIE exposure versus MI symptoms). Although the MIES includes 3 items assessing unspecified distress stemming from specific PMIE exposures, we considered it to primarily be a measure assessing military-related PMIE exposures. One study^2,23^ reported total scores for the Brief Moral Injury Screen (BMIS), which assesses both PMIE exposures and MI symptoms. These data were included for both analyses.

Table 1 Categorization of Assessment of PMIE Exposure or MI Symptoms for Synthesis

PMIE Exposure | MI Symptoms
BMIS – Total score | BMIS – Total score
MIES – Total score or subscales | EMIS-M – Total score or subscales
MIQ-M | MIS
Studies reporting frequency of PMIE exposures without a measure | MISS-M or MISS-M-SF
Studies reporting frequency of PMIE exposures without a measure | Modified MIQ-M^a^
Studies categorizing traumatic events as PMIE exposures without a measure | Use of items from non-MI scales to assess symptoms of MI^b^

Notes.

a Includes 5 items assessing MI symptoms for each exposure item

b One study used items from the DES-IV and DRRI-2 to assess the MI symptoms of sorrow, regret, shame, and alienation.

Abbreviations. BMIS=Brief Moral Injury Screen; EMIS-M=Expressions of Moral Injury Scale – Military Version; MI=moral injury; MIES=Moral Injury Events Scale; MIQ-M=Moral Injury Questionnaire – Military Version; MIS=Moral Injury Scale; MISS-M=Moral Injury Symptom Scale – Military Version; MISS-M-SF= Moral Injury Symptom Scale – Military Version – short form.

Correlations for each mental health outcome were pooled using multilevel random-effects meta-analyses, given that studies frequently reported multiple correlations for the same outcome type (ie, dependent estimates). Common examples of dependency included reporting of both patient and clinician assessments of the same outcome or multiple subscales of a PMIE exposure or MI symptom measure. A correlation of 0.9 was assumed among dependent estimates. One exception to this approach was when studies reported estimates from multiple comparable measures of a similarly defined outcome in identical samples (eg, past-month PTSD symptom severity assessed with 2 self-report measures). In these cases, we included data from only 1 measure in meta-analyses (typically the most commonly used measure across studies). Another exception was when studies assessed PMIE exposure or MI symptoms using multiple versions of the same measure (eg, a full version and a developmental short-form version). In this scenario, we included data from only the full or better-established measure.

Variation in correlations across studies (heterogeneity) was estimated using restricted maximum-likelihood estimation and is presented as 95% prediction intervals (PIs). Prediction intervals describe the likeliest range of true associations (eg, true correlations between MI symptoms and outcomes) across studies and provide an estimate of the magnitude and direction of associations that would be found in future studies similar to those included in a synthesis.^24^ A prediction interval encompassing values similar to the overall estimate suggests limited heterogeneity, whereas an interval that includes estimates in the same direction as the overall estimate but that vary widely in magnitude (eg, small to large positive correlations) suggests moderate heterogeneity. If a prediction interval encompasses estimates that range widely in both magnitude and direction, then substantial heterogeneity is likely present. Prediction intervals were evaluated alongside forest plots (provided in the Appendix) to reach conclusions about whether correlations included in a given analysis were consistent, moderately inconsistent, or highly inconsistent.

All meta-analyses were conducted using the metafor^25^ package for R (R Foundation for Statistical Computing, Vienna, Austria). For meta-analyses involving fewer than 20 correlations, a more conservative t-distribution was used for 95% confidence intervals and significant tests. When fewer than 3 comparable studies were available for a given outcome—or studies were judged to be too disparate in methodological or participant characteristics—we described evidence narratively.

### Strength of Evidence

After synthesizing available evidence, we rated the strength of evidence (SOE) for each outcome based on the methodology and risk of bias of available studies, the consistency and certainty of findings, and the directness of outcomes (whether reported outcomes are relevant to patients and providers).^26^ We used the following general algorithm: high strength evidence consisted of multiple studies with consistent and precise findings at low risk of bias, and clinically relevant outcomes; moderate strength evidence consisted of multiple studies with consistent and precise findings at low to moderate risk of bias, and clinically relevant outcomes; low strength evidence consisted of a single study, or multiple studies, with moderate to high risk of bias, inconsistent or imprecise findings, and/or outcomes with limited clinical relevance; and insufficient evidence consisted of a single study with moderate or high risk of bias, or no available studies.

Before assigning final SOE ratings, we considered the relative contribution of individual studies. For example, if a study was at high risk of bias but made up a relatively small proportion of available evidence for an outcome and/or reported results that were generally consistent with more rigorous studies of the same outcome, we did not downgrade the SOE rating simply because of the presence of that high risk of bias study. Conclusions using likely (eg, “Greater MI symptoms are likely associated with increases in PTSD symptoms”) are based on moderate strength evidence, while those using may are based on low strength evidence. Because of the correlational nature of most available evidence, we did not attempt to draw conclusions about the causal direction of relationships between PMIE/MI and outcomes (eg, “Greater MI symptoms likely increase PTSD symptoms").