# BACKGROUND

Military service members may be exposed to unanticipated, ambiguous, and stressful situations in which their own actions or the actions of others conflict with deeply held values. Moral injury (MI) describes a uniquely intense and distressing response to such exposures, which are referred to as potentially morally injurious events (PMIEs). MI is characterized by feelings of guilt and shame, loss of trust, and loss of meaning or purpose. Over the past 2 decades, increased clinical and research interest has focused on the impacts of PMIEs, and whether exposure to such events ultimately produces a cluster of psychological, emotional, behavioral, spiritual, and social symptoms distinct from other recognized psychiatric conditions.^1^ While initially described for military service members who experienced war, the concept of MI has increasingly been applied to other populations encountering morally ambiguous situations. For example, the concept of MI has been evoked for health care workers attempting to deliver care under resource-constrained conditions and while facing personal health risks during the peak of the COVID-19 pandemic.^2^

PMIEs have been conceptualized as fitting into several broad categories: moral transgressions related to self-directed actions (commissions) or inactions (omissions) and other-directed actions including witnessing or being a victim of others’ transgressions and leadership betrayal.^1,3^ Commonly cited examples of PMIEs in a wartime setting include witnessing or perpetrating atrocities, killing in combat, feeling betrayed by military leadership, or witnessing human suffering.^1^ Studies have documented that between 24%^4^ to 40%^5^ of deployed service members report exposure to at least 1 of these events. PMIEs and MI share a similar relationship to that of trauma and PTSD, with a PMIE being a necessary but not sufficient requirement for the development of MI. However, unlike the traumatic exposure requirement for PTSD (exposure to death, threatened death, actual or threatened serious injury, or actual or threatened sexual violence), there is a lack of agreement on the specific PMIE criteria and whether there is an exposure threshold to qualify for an MI syndrome.

Interest in MI has arisen, in part, from the observation that established PTSD criteria may not adequately characterize a unique set of symptoms seemingly related to morally injurious stressors. Accordingly, it has been speculated that combat-related PTSD may be more treatment refractory (compared with PTSD due to non-combat traumas) because conventional PTSD treatments inadequately address MI-specific responses like guilt and shame.^6^ Shay^7^ first introduced the concept of MI in his 1994 book, drawing metaphoric parallels between the internal struggles of Vietnam Veterans and the experiences described in Homer’s Iliad, particularly those involving leadership betrayal. In 2009, Litz et al^1^ proposed the first conceptual model and definition of MI, aiming to promote more empirical research on MI that could inform treatment. Research on MI has proliferated since these initial publications, but despite this growth, consensus has not been reached on definitions of PMIEs and MI, nor on the most accurate and useful measures of MI-related constructs.^8–10^

Numerous definitions of MI have been proposed,^11,12^ with a recent systematic review identifying 12 different published definitions of MI, only 2 of which were based on empirical evidence.^12^ At the present time, there is no gold standard measure of MI or agreed upon clinical definition for confirming the presence of MI. A number of measures have been developed that assess PMIE exposures, MI outcomes, or both. Several measures include an assessment of PMIE exposures with corollary items to assess MI, and as a result, studies have differed in whether they employ the measures as predictors of outcomes or as outcomes themselves.^8,9,13^ Importantly, when PMIE exposure and MI outcomes are measured separately, the constructs are often highly (though not perfectly) correlated.^14,15^ This suggests a relationship between the experience of PMIEs and the development of guilt, shame, and other responses characteristic of MI.

Until recently, measures of PMIE exposure and MI outcomes were developed mostly by psychologists who generated items based on their clinical experience or compiled items from existing scales, raising concerns about the validity of these measures.^16^ A systematic review of measures of MI and moral distress^10^ that assessed 7 domains of reliability and validity found that convergent and divergent validity were not examined for most measures, and most assessed PMIE exposures and outcomes together. The Moral Injury Events Scale (MIES) is the oldest and most often used measure to assesses military-related PMIE exposures, although it has also been used to measure MI given the inclusion of 3 items assessing unspecified distress. Older measures assessing MI outcomes, such as the Moral Injury Symptom Scale (MISS) and Expressions of Moral Injury Scale (EMIS), do not index MI outcomes to PMIE exposures. Newer measures, such as the Moral Injury Outcomes Scale (MIOS), have been developed in recent years to overcome issues with validity and conceptual clarity present with earlier measures.

MI-related constructs have been linked to adverse psychosocial outcomes among Veterans and military service members.^17,18^ For example, Wisco et al^5^ found that exposure to PMIEs was associated with mental health disorders and suicidal ideation and attempts among a large national sample of US Veterans of the Iraq and Afghanistan wars. Transgressions by self were associated with suicidal ideation, while betrayal was associated with post-deployment suicide attempts. Bryan et al^19^ found that transgressions by self and transgressions by others were more predictive of a lifetime history of a suicide attempt relative to betrayal in a sample of active duty service members. Other studies have demonstrated that Veterans suffering from both MI symptoms and PTSD may experience higher rates of suicide attempts relative to either condition alone.^20^

The VA Integrative Mental Health (IMH) initiative, supported by the VHA Office of Mental Health and Suicide Prevention (OMHSP), requested the present review, which aimed to characterize published literature on moral injury broadly across populations and to synthesize available evidence on the relationship between PMIE and MI and mental health outcomes among a more narrowly defined subset of US Veterans and military service members. IMH’s Understanding Moral Injury project is working to address Section 506a of the STRONG Veterans Act (H.R. 6411), which directs VA to conduct research on how MI relates to the mental health needs of Veterans who served in the Armed Forces after September 11, 2001, and to identify best practices for mental health treatment among these Veterans. Findings from this review will inform these efforts and help guide VA research on PMIE and MI.