# Appendix

## SEARCH STRATEGIES

Search Date: 02/12/24 | | Search Statement | | Results
MEDLINE; Ovid MEDLINE(R) and Epub Ahead of Print, In-Process, In-Data-Review & Other Non-Indexed Citations and Daily 1946 to February 09, 2024 | 1 | (moral adj3 injur*).ti,ab,kf | | 790
MEDLINE; Ovid MEDLINE(R) and Epub Ahead of Print, In-Process, In-Data-Review & Other Non-Indexed Citations and Daily 1946 to February 09, 2024 | 2 | limit 1 to English language | | 779
MEDLINE; Ovid MEDLINE(R) and Epub Ahead of Print, In-Process, In-Data-Review & Other Non-Indexed Citations and Daily 1946 to February 09, 2024 | 3 | limit 2 to year=”2009-Current” | | 775
MEDLINE; Ovid MEDLINE(R) and Epub Ahead of Print, In-Process, In-Data-Review & Other Non-Indexed Citations and Daily 1946 to February 09, 2024
MEDLINE; Ovid MEDLINE(R) and Epub Ahead of Print, In-Process, In-Data-Review & Other Non-Indexed Citations and Daily 1946 to February 09, 2024
MEDLINE; Ovid MEDLINE(R) and Epub Ahead of Print, In-Process, In-Data-Review & Other Non-Indexed Citations and Daily 1946 to February 09, 2024
MEDLINE; Ovid MEDLINE(R) and Epub Ahead of Print, In-Process, In-Data-Review & Other Non-Indexed Citations and Daily 1946 to February 09, 2024
APA PsycInfo; 1967 to February Week 2 2024 | 1 | (moral adj3 injur*).ti,ab | | 764
APA PsycInfo; 1967 to February Week 2 2024 | 2 | limit 1 to English language | | 716
APA PsycInfo; 1967 to February Week 2 2024 | 3 | limit 2 to year=”2009-Current” | | 711
APA PsycInfo; 1967 to February Week 2 2024
| | | Total | 1486
| | | Total after deduplication | 1179

## STUDIES EXCLUDED DURING FULL-TEXT SCREENING

Citation | Exclude Reason
Benfer N, Vannini MBN, Grunthal B, Moral injury symptoms and related problems among service members and Veterans: A network analysis. Journal of Military, Veteran and Family Health. 2023;9(2):52–71. doi:10.3138/jmvfh-2022-0040 42533897 | Ineligible setting
Biscoe N, Bonson A, Nickerson A, Murphy D. Factors associated with exposure to potentially morally injurious events (PMIEs) and moral injury in a clinical sample of veterans. European Journal of Trauma & Dissociation. 2023;7(3). doi:10.1016/j.ejtd.2023.100343 | Ineligible setting
Houtsma C, Khazem LR, Green BA, Anestis MD. Isolating effects of moral injury and low post-deployment support within the U.S. military. Psychiatry research. 2017;247(qc4, 7911385):194–199. doi:10.1016/j.psychres.2016.11.031 27918969 | Ineligible outcome
Martin RL, Houtsma C, Bryan AO, Bryan CJ, Green BA, Anestis MD. The impact of aggression on the relationship between betrayal and belongingness among U.S. military personnel. Military Psychology. 2017;29(4):271–282. doi:10.1037/mil0000160 | Ineligible outcome
Mensink B, van Schagen A, van der Aa N, Ter Heide FJJ. Moral Injury in Trauma-Exposed, Treatment-Seeking Police Officers and Military Veterans: Latent Class Analysis. Frontiers in psychiatry. 2022;13(101545006):904659. doi:10.3389/fpsyt.2022.904659 35898627 | Ineligible population
Morgan L, Beattie D, Irons C, Ononaiye M. The role of compassion in moral injury among military veterans: Implications for treatment. Psychological trauma: theory, research, practice and policy. 2024;(101495376). doi:10.1037/tra0001646 | Ineligible setting
Murphy D, Karatzias T, Busuttil W, Greenberg N, Shevlin M. ICD-11 posttraumatic stress disorder (PTSD) and complex PTSD (CPTSD) in treatment seeking veterans: risk factors and comorbidity. Social psychiatry and psychiatric epidemiology. 2021;56(7):1289–1298. doi:10.1007/s00127-021-02028-6 33464398 | Ineligible setting
Russell B, Mussap AJ. Rumination and threat-biased interpretation mediate posttraumatic stress and growth responses to military stressors. Military psychology: the official journal of the Division of Military Psychology, American Psychological Association. 2023;35(5):451–466. doi:10.1080/08995605.2022.2127618 37615560 | Ineligible setting
Smigelsky MA, Malott JD, Veazey Morris K, Berlin KS, Neimeyer RA. Latent profile analysis exploring potential moral injury and posttraumatic stress disorder among military veterans. Journal of clinical psychology. 2019;75(3):499–519. doi:10.1002/jclp.22714 30431152 | Ineligible outcome
Smith-MacDonald L, Jones C, Brown MRG, Moving Forward from Moral Injury: A Mixed Methods Study Investigating the Use of 3MDR for Treatment-Resistant PTSD. International journal of environmental research and public health. 2023;20(7). doi:10.3390/ijerph20075415 | Ineligible setting
Williamson V, Murphy D, Stevelink SA, Jones E, Allen S, Greenberg N. Family and occupational functioning following military trauma exposure and moral injury. BMJ military health. 2023;169(3):205–211. doi:10.1136/bmjmilitary-2020-001770 33685904 | Ineligible setting

## REFERENCES OF INCLUDED STUDIES FOR KEY QUESTION 1

### REVIEWS

1 Aita SL, Kondrath SR, Owen T, Borgogna NC, Usset TJ. The Status of Evidence-Based Treatments for Moral Injury Syndrome: Review and Meta-analysis of Randomized Controlled Trials. Curr Treat Options Psych. 2023;10(3):217–233. doi:10.1007/s40501-023-00292-8
2 Brémault-Phillips S, Pike A, Scarcella F, Cherwick T. Spirituality and Moral Injury Among Military Personnel: A Mini-Review. Front Psychiatry. 2019;10:276. doi:10.3389/fpsyt.2019.00276 31110483
3 Carey LB, Hodgson TJ, Krikheli L, Moral Injury, Spiritual Care and the Role of Chaplains: An Exploratory Scoping Review of Literature and Resources. J Relig Health. 2016;55(4):1218–1245. doi:10.1007/s10943-016-0231-x 27094705
4 Čartolovni A, Stolt M, Scott PA, Suhonen R. Moral injury in healthcare professionals: A scoping review and discussion. Nurs Ethics. 2021;28(5):590–602. doi:10.1177/0969733020966776 33427020
5 Chew QH, Lee TS, Sim K. Moral injury and associated context, contributors and consequences within mental healthcare professionals: a scoping review. Postgraduate Medicine. 2023;135(7):646–668. doi:10.1080/00325481.2023.2266007 37776227
6 Coimbra BM, Zylberstajn C, Van Zuiden M, Moral injury and mental health among healthcare workers during the COVID-19 pandemic: meta-analysis. European Journal of Psychotraumatology. 2024;15(1):2299659. doi:10.1080/20008066.2023.2299659
7 Griffin BJ, Purcell N, Burkman K, Moral Injury: An Integrative Review. Journal of Traumatic Stress. 2019;32(3):350–362. doi:10.1002/jts.22362 30688367
8 Griffin BJ, Weber MC, Hinkson KD, Toward a Dimensional Contextual Model of Moral Injury: A Scoping Review on Healthcare Workers. Curr Treat Options Psych. 2023;10(3):199–216. doi:10.1007/s40501-023-00296-4
9 Haight W, Sugrue E, Calhoun M, Black J. A scoping study of moral injury: Identifying directions for social work research. Children and Youth Services Review. 2016;70:190–200. doi:10.1016/j.childyouth.2016.09.026
10 Hall NA, Everson AT, Billingsley MR, Miller MB. Moral injury, mental health and behavioural health outcomes: A systematic review of the literature. Clin Psychology and Psychoth. 2022;29(1):92–110. doi:10.1002/cpp.2607
11 Houle SA, Ein N, Gervasio J, Measuring moral distress and moral injury: A systematic review and content analysis of existing scales. Clinical Psychology Review. 2024;108:102377. doi:10.1016/j.cpr.2023.102377 38218124
12 Jack FJG, Kotronoulas G. The Perceptions of Healthcare Staff Regarding Moral Injury and the Impact on Staff Life and Work During COVID-19: A Scoping Review of International Evidence. J Relig Health. 2023;62(4):2836–2860. doi:10.1007/s10943-023-01803-w 37027110
13 Jamieson N, Carey LB, Jamieson A, Maple M. Examining the Association Between Moral Injury and Suicidal Behavior in Military Populations: A Systematic Review. J Relig Health. 2023;62(6):3904–3925. doi:10.1007/s10943-023-01885-6 37592186
14 Jones KA, Freijah I, Carey L, Moral Injury, Chaplaincy and Mental Health Provider Approaches to Treatment: A Scoping Review. J Relig Health. 2022;61(2):1051–1094. doi:10.1007/s10943-022-01534-4 35290554
15 Kendall-Tackett K, Beck CT. Secondary Traumatic Stress and Moral Injury in Maternity Care Providers: A Narrative and Exploratory Review. Front Glob Womens Health. 2022;3:835811. doi:10.3389/fgwh.2022.835811 35602853
16 Khan AJ, Griffin BJ, Maguen S. A Review of Research on Moral Injury and Suicide Risk. Curr Treat Options Psych. 2023;10(3):259–287. doi:10.1007/s40501-023-00293-7
17 Koenig HG, Youssef NA, Pearce M. Assessment of Moral Injury in Veterans and Active Duty Military Personnel With PTSD: A Review. Front Psychiatry. 2019;10:443. doi:10.3389/fpsyt.2019.00443 31316405
18 Laher Z, Robertson N, Harrad-Hyde F, Jones CR. Prevalence, Predictors, and Experience of Moral Suffering in Nursing and Care Home Staff during the COVID-19 Pandemic: A Mixed-Methods Systematic Review. IJERPH. 2022;19(15):9593. doi:10.3390/ijerph19159593 35954948
19 Lentz LM, Smith-MacDonald L, Malloy D, Carleton RN, Brémault-Phillips S. Compromised Conscience: A Scoping Review of Moral Injury Among Firefighters, Paramedics, and Police Officers. Front Psychol. 2021;12:639781. doi:10.3389/fpsyg.2021.639781 33868111
20 McEwen C, Alisic E, Jobson L. Moral injury and mental health: A systematic review and meta-analysis. Traumatology. 2021;27(3):303–315. doi:10.1037/trm0000287
21 Nazarov A, Jetly R, McNeely H, Kiang M, Lanius R, McKinnon MC. Role of morality in the experience of guilt and shame within the armed forces. Acta Psychiatr Scand. 2015;132(1):4–19. doi:10.1111/acps.12406 25737392
22 Richardson NM, Lamson AL, Smith M, Eagan SM, Zvonkovic AM, Jensen J. Defining Moral Injury Among Military Populations: A Systematic Review. Journal of Traumatic Stress. 2020;33(4):575–586. doi:10.1002/jts.22553 32567119
23 Riedel PL, Kreh A, Kulcar V, Lieber A, Juen B. A Scoping Review of Moral Stressors, Moral Distress and Moral Injury in Healthcare Workers during COVID-19. IJERPH. 2022;19(3):1666. doi:10.3390/ijerph19031666 35162689
24 Stovall M, Hansen L, Van Ryn M. A Critical Review: Moral Injury in Nurses in the Aftermath of a Patient Safety Incident. J of Nursing Scholarship. 2020;52(3):320–328. doi:10.1111/jnu.12551
25 Thibodeau PS, Nash A, Greenfield JC, Bellamy JL. The Association of Moral Injury and Healthcare Clinicians’ Wellbeing: A Systematic Review. IJERPH. 2023;20(13):6300. doi:10.3390/ijerph20136300 37444147
26 Webb EL, Ireland JL, Lewis M, Morris D. Potential Sources of Moral Injury for Healthcare Workers in Forensic and Psychiatric Settings: A Systematic Review and Meta-ethnography. Trauma, Violence, & Abuse. 2024;25(2):918–934. doi:10.1177/15248380231167390
27 Williamson V, Stevelink SAM, Greenberg N. Occupational moral injury and mental health: systematic review and meta-analysis. Br J Psychiatry. 2018;212(6):339–346. doi:10.1192/bjp.2018.55 29786495
28 Wilson MA, Shay A, Harris JI, Faller N, Usset TJ, Simmons A. Moral Distress and Moral Injury in Military Healthcare Clinicians: A Scoping Review. AJPM Focus. 2024;3(2):100173. doi:10.1016/j.focus.2023.100173 38304024
29 Xue Y, Lopes J, Ritchie K, Potential Circumstances Associated With Moral Injury and Moral Distress in Healthcare Workers and Public Safety Personnel Across the Globe During COVID-19: A Scoping Review. Front Psychiatry. 2022;13:863232. doi:10.3389/fpsyt.2022.863232 35770054

### PRIMARY STUDIES

1 Adeyemo OO, Tu S, Falako S, Keene D. Stressors on frontline healthcare workers during the COVID-19 pandemic: a focus on moral injury and implications for the future. International archives of occupational and environmental health. 2022;95(8):1755–1762. doi:10.1007/s00420-022-01867-3 35482111
2 Akhtar M, Faize FA, Malik RZ, Tabusam A. Moral injury and psychological resilience among healthcare professionals amid COVID-19 pandemic. Pakistan journal of medical sciences. 2022;38(5):1338–1342. doi:10.12669/pjms.38.5.5122 35799754
3 Ames D, Erickson Z, Geise C, Treatment of Moral Injury in U.S. Veterans with PTSD Using a Structured Chaplain Intervention. Journal of religion and health. 2021;60(5):3052–3060. doi:10.1007/s10943-021-01312-8 34148181
4 Ames D, Erickson Z, Youssef NA, Moral Injury, Religiosity, and Suicide Risk in U.S. Veterans and Active Duty Military with PTSD Symptoms. Military Medicine. 2018;184(3–4):e271–e278. doi:10.1093/milmed/usy148
5 Amsalem D, Lazarov A, Markowitz JC, Psychiatric symptoms and moral injury among US healthcare workers in the COVID-19 era. BMC psychiatry. 2021;21(1):546. doi:10.1186/s12888-021-03565-9 34740357
6 Andrews K, Lloyd CS, Densmore M, “I am afraid you will see the stain on my soul”: Direct gaze neural processing in individuals with PTSD after moral injury recall. Social cognitive and affective neuroscience. 2023;18(1). doi:10.1093/scan/nsad053
7 Andrews K, Roth SL, Lloyd C, Development and preliminary evaluation of the Moral Injury Assessment for survivors of abuse. Traumatology. 2023;30(4):739–748. doi:10.1037/trm0000475
8 Andrukonis A, Protopopova A. Occupational health of animal shelter employees by live release rate, shelter type, and euthanasia-related decision. Anthrozoos. 2020;33(1):119–131. doi:10.1080/08927936.2020.1694316
9 Antal CJ, Yeomans PD, East R, Transforming veteran identity through community engagement: A chaplain-psychologist collaboration to address moral injury. Journal of Humanistic Psychology. 2023;63(6):801–826. doi:10.1177/0022167819844071
10 Artra iishana P. Transparent assessment: Discovering authentic meanings made by combat veterans. Journal of Constructivist Psychology. 2014;27(3):211–235. doi:10.1080/10720537.2014.904704
11 Ashwal-Malka A, Tal-Kishner K, Feingold D. Moral injury and cannabis use disorder among Israeli combat veterans: The role of depression and perceived social support. Addictive behaviors. 2022;124(2gw, 7603486):107114. doi:10.1016/j.addbeh.2021.107114 34543870
12 Balmer BR, Sippola J, Beehler S. Processes and outcomes of a communalization of trauma approach: Vets & Friends community-based support groups. Journal of community psychology. 2021;49(7):2764–2780. doi:10.1002/jcop.22516 33506966
13 Battaglia AM, Protopopescu A, Boyd JE, The relation between adverse childhood experiences and moral injury in the Canadian Armed Forces. European journal of psychotraumatology. 2019;10(1):1546084. doi:10.1080/20008198.2018.1546084 30693070
14 Battles AR, Bravo AJ, Kelley ML, White TD, Braitman AL, Hamrick HC. Moral injury and PTSD as mediators of the associations between morally injurious experiences and mental health and substance use. Traumatology. 2018;24(4):246–254. doi:10.1037/trm0000153
15 Battles AR, Kelley ML, Jinkerson JD, C Hamrick H, F Hollis B. Associations Among Exposure to Potentially Morally Injurious Experiences, Spiritual Injury, and Alcohol Use Among Combat Veterans. Journal of traumatic stress. 2019;32(3):405–413. doi:10.1002/jts.22404 31169954
16 Beck CT. Secondary Qualitative Analysis of Moral Injury in Obstetric and Neonatal Nurses. Journal of obstetric, gynecologic, and neonatal nursing: JOGNN. 2022;51(2):166–176. doi:10.1016/j.jogn.2021.12.003 35114167
17 Bekes V, Szabo D, Levay EE, Salgo E, Unoka Z. Moral Injury and Shame Mediate the Relationship Between Childhood Trauma and Borderline Personality Disorder, PTSD, and Complex PTSD Symptoms in Psychiatric Inpatients. Journal of personality disorders. 2023;37(4):406–423. doi:10.1521/pedi.2023.37.4.406 37721777
18 Benatov J, Zerach G, Levi-Belz Y. Moral injury, depression, and anxiety symptoms among health and social care workers during the COVID-19 pandemic: The moderating role of belongingness. The International journal of social psychiatry. 2022;68(5):1026–1035. doi:10.1177/00207640221099421 35634658
19 Benfer N, Vannini MBN, Grunthal B, Moral injury symptoms and related problems among service members and Veterans: A network analysis. Journal of Military, Veteran and Family Health. 2023;9(2):52–71. doi:10.3138/jmvfh-2022-0040 42533897
20 Berdida DJE. The mediating roles of moral courage and moral resilience between nurses’ moral distress and moral injury: An online cross-sectional study. Nurse education in practice. 2023;71(101090848):103730. doi:10.1016/j.nepr.2023.103730 37499534
21 Berdida DJE, Grande RAN. Moral Distress, Moral Resilience, Moral Courage, and Moral Injury Among Nurses in the Philippines During the COVID-19 Pandemic: A Mediation Analysis. Journal of religion and health. 2023;62(6):3957–3978. doi:10.1007/s10943-023-01873-w 37442900
22 Bhalla A, Allen E, Renshaw K, Kenny J, Litz B. Emotional numbing symptoms partially mediate the association between exposure to potentially morally injurious experiences and sexual anxiety for male service members. Journal of trauma & dissociation: the official journal of the International Society for the Study of Dissociation (ISSD). 2018;19(4):417–430. doi:10.1080/15299732.2018.1451976 29601288
23 Biscoe N, Bonson A, Nickerson A, Murphy D. Factors associated with exposure to potentially morally injurious events (PMIEs) and moral injury in a clinical sample of veterans. European Journal of Trauma & Dissociation. 2023;7(3). doi:10.1016/j.ejtd.2023.100343
24 Bonson A, Murphy D, Aldridge V, Greenberg N, Williamson V. Veterans’ experiences of moral injury, treatment and recommendations for future support. BMJ military health. 2023;(101761581). doi:10.1136/military-2022-002332
25 Borges LM. A service member’s experience of Acceptance and Commitment Therapy for Moral Injury (ACT-MI) via telehealth: “Learning to accept my pain and injury by reconnecting with my values and starting to live a meaningful life”. Journal of Contextual Behavioral Science. 2019;13:134–140. doi:10.1016/j.jcbs.2019.08.002
26 Borges LM, Bahraini NH, Holliman BD, Gissen MR, Lawson WC, Barnes SM. Veterans’ perspectives on discussing moral injury in the context of evidence-based psychotherapies for PTSD and other VA treatment. Journal of clinical psychology. 2020;76(3):377–391. doi:10.1002/jclp.22887 31714610
27 Borges LM, Holliday R, Barnes SM, A longitudinal analysis of the role of potentially morally injurious events on COVID-19-related psychosocial functioning among healthcare providers. PloS one. 2021;16(11):e0260033. doi:10.1371/journal.pone.0260033 34767617
28 Borges LM, Holliman BD, Farnsworth JK, Barnes SM. Perceptions of Military Experience Among Veterans Reporting Lifetime Warzone Moral Injury. The Journal of nervous and mental disease. 2023;211(10):796–801. doi:10.1097/NMD.0000000000001676 37782522
29 Boscarino JA, Adams RE, Wingate TJ, Impact and Risk of Moral Injury Among Deployed Veterans: Implications for Veterans and Mental Health. Frontiers in psychiatry. 2022;13(101545006):899084. doi:10.3389/fpsyt.2022.899084 35733800
30 Boska RL, Capron DW. Exploring the maladaptive cognitions of moral injury within a primarily combat-trauma military sample. Psychological trauma: theory, research, practice and policy. 2021;13(8):861–868. doi:10.1037/tra0001071 34435814
31 Bow SMA, Schroder-Back P, Norcliffe-Brown D, Wilson J, Tahzib F. Moral distress and injury in the public health professional workforce during the COVID-19 pandemic. Journal of public health (Oxford, England). 2023;45(3):697–705. doi:10.1093/pubmed/fdad010 36866402
32 Braitman AL, Battles AR, Kelley ML, Psychometric Properties of a Modified Moral Injury Questionnaire in a Military Population. Traumatology. 2018;24(4):301–312. doi:10.1037/trm0000158 30546271
33 Bravo AJ, Kelley ML, Mason R, Ehlke S, Vinci C, Redman Ret LJC. Rumination as a Mediator of the Associations Between Moral Injury and Mental Health Problems in Combat-Wounded Veterans. Traumatology. 2020;26(1):52–60. doi:10.1037/trm0000198 32863781
34 Brennan CJ, McKay MT, Cole JC. Morally injurious events and post-traumatic embitterment disorder in UK health and social care professionals during COVID-19: a cross-sectional web survey. BMJ open. 2022;12(5):e054062. doi:10.1136/bmjopen-2021-054062
35 Bryan AO, Bryan CJ, Morrow CE, Etienne N, Ray-Sannerud B. Moral injury, suicidal ideation, and suicide attempts in a military sample. Traumatology. 2014;20(3):154–160. doi:10.1037/h0099852
36 Bryan CJ, Bryan AO, Anestis MD, Measuring Moral Injury: Psychometric Properties of the Moral Injury Events Scale in Two Military Samples. Assessment. 2016;23(5):557–570. doi:10.1177/1073191115590855 26092043
37 Bryan CJ, Bryan AO, Roberge E, Leifker FR, Rozek DC. Moral injury, posttraumatic stress disorder, and suicidal behavior among National Guard personnel. Psychological trauma: theory, research, practice and policy. 2018;10(1):36–45. doi:10.1037/tra0000290 28581315
38 Cameron AY, Eaton E, Brake CA, Capone C. Moral injury as a unique predictor of suicidal ideation in a veteran sample with a substance use disorder. Psychological trauma: theory, research, practice and policy. 2021;13(8):856–860. doi:10.1037/tra0000988 33370139
39 Campbell BM, Knipp MA, Anwar SS, Hoopsick RA. Moral injury and substance use among United States healthcare workers. Stress and health: journal of the International Society for the Investigation of Stress. 2023;(101089166). doi:10.1002/smi.3321
40 Cenkner DP, Usman H, Zalta AK. Differential associations of rumination and cognitive flexibility with guilt and shame following potentially morally injurious events. Journal of affective disorders. 2023;325(h3v, 7906073):135–140. doi:10.1016/j.jad.2022.12.165 36621679
41 Cenkner DP, Yeomans PD, Antal CJ, Scott JC. A Pilot Study of a Moral Injury Group Intervention Co-Facilitated by a Chaplain and Psychologist. Journal of traumatic stress. 2021;34(2):367–374. doi:10.1002/jts.22642 33373486
42 Chandrabhatla T, Asgedom H, Gaudiano ZP, Second victim experiences and moral injury as predictors of hospitalist burnout before and during the COVID-19 pandemic. PloS one. 2022;17(10):e0275494. doi:10.1371/journal.pone.0275494 36194588
43 Chaplo SD, Kerig PK, Wainryb C. Development and Validation of the Moral Injury Scales for Youth. Journal of traumatic stress. 2019;32(3):448–458. doi:10.1002/jts.22408 31162746
44 Chesnut RP, Richardson CB, Morgan NR, Moral Injury and Social Well-Being: A Growth Curve Analysis. Journal of traumatic stress. 2020;33(4):587–597. doi:10.1002/jts.22567 32662166
45 Chesnut RP, Richardson CB, Morgan NR, Bleser JA, Mccarthy KJ, Perkins DF. The Moral Injury Symptoms Scale-Military Version-Short Form: Further Scale Validation in a U.S. Veteran Sample. Journal of religion and health. 2022;61(4):3384–3401. doi:10.1007/s10943-022-01606-5 35790578
46 Cole AC, Smirnova MO, Yang Y, Lancaster CL. Longitudinal associations between moral injury perceptions and mental health among healthcare workers during the pandemic. Psychological trauma: theory, research, practice and policy. 2023;(101495376). doi:10.1037/tra0001594
47 Cooper-Bribiesca D, Rascon-Martinez DM, Miguel-Puga JA, Physicians’ Distress Related to Moral Issues and Mental Health In-Between Two Late Waves of COVID-19 Contagions. International journal of environmental research and public health. 2023;20(5). doi:10.3390/ijerph20053989
48 Corona CD, Van Orden KA, Wisco BE, Pietrzak RH. Meaning in life moderates the association between morally injurious experiences and suicide ideation among U.S. combat veterans: Results from the National Health and Resilience in Veterans Study. Psychological Trauma: Theory, Research, Practice, and Policy. 2019;11(6):614–620. doi:10.1037/tra0000475 31144841
49 Cox M, Skjolsvik V, Rathfon B, Buckner E. Moral Injury in Veterans: Application of the Roy Adaptation Model to Improve Coping. ANS Advances in nursing science. 2021;44(3):224–237. doi:10.1097/ANS.0000000000000348 34397479
50 Currier JM, Farnsworth JK, Drescher KD, McDermott RC, Sims BM, Albright DL. Development and evaluation of the Expressions of Moral Injury Scale-Military Version. Clinical psychology & psychotherapy. 2018;25(3):474–488. doi:10.1002/cpp.2170 29282787
51 Currier JM, Foster JD, Isaak SL. Moral Injury and Spiritual Struggles in Military Veterans: A Latent Profile Analysis. Journal of traumatic stress. 2019;32(3):393–404. doi:10.1002/jts.22378 30861209
52 Currier JM, Foster JD, Karatzias T, Murphy D. Moral injury and ICD-11 complex PTSD (CPTSD) symptoms among treatment-seeking veterans in the United Kingdom. Psychological trauma: theory, research, practice and policy. 2021;13(4):417–421. doi:10.1037/tra0000921 33475402
53 Currier JM, Holland JM, Drescher K, Foy D. Initial psychometric evaluation of the Moral Injury Questionnaire--Military version. Clinical psychology & psychotherapy. 2015;22(1):54–63. doi:10.1002/cpp.1866 24022873
54 Currier JM, Holland JM, Malott J. Moral injury, meaning making, and mental health in returning veterans. Journal of clinical psychology. 2015;71(3):229–240. doi:10.1002/jclp.22134 25331653
55 Currier JM, Isaak SL, McDermott RC. Validation of the Expressions of Moral Injury Scale-Military version-Short Form. Clinical psychology & psychotherapy. 2020;27(1):61–68. doi:10.1002/cpp.2407 31657075
56 Currier JM, McCormick W, Drescher KD. How do morally injurious events occur? A qualitative analysis of perspectives of veterans with PTSD. Traumatology. 2015;21(2):106–116. doi:10.1037/trm0000027
57 Currier JM, McDermott RC, Farnsworth JK, Borges LM. Temporal Associations Between Moral Injury and Posttraumatic Stress Disorder Symptom Clusters in Military Veterans. Journal of traumatic stress. 2019;32(3):382–392. doi:10.1002/jts.22367 30715755
58 Currier JM, McDermott RC, Fernandez P, Examining the outcomes and acceptability of a peer-led spiritual intervention for moral injury in a veteran service organization. Psychological services. 2023;(101214316). doi:10.1037/ser0000762
59 D’Alessandro-Lowe AM, Karram M, Ritchie K, Coping, Supports and Moral Injury: Spiritual Well-Being and Organizational Support Are Associated with Reduced Moral Injury in Canadian Healthcare Providers during the COVID-19 Pandemic. International journal of environmental research and public health. 2023;20(19). doi:10.3390/ijerph20196812
60 D’Alessandro-Lowe AM, Patel H, Easterbrook B, The independent and combined impact of moral injury and moral distress on post-traumatic stress disorder symptoms among healthcare workers during the COVID-19 pandemic. European journal of psychotraumatology. 2024;15(1):2299661. doi:10.1080/20008066.2023.2299661 38334706
61 Dale LP, Cuffe SP, Sambuco N, Morally Distressing Experiences, Moral Injury, and Burnout in Florida Healthcare Providers during the COVID-19 Pandemic. International journal of environmental research and public health. 2021;18(23). doi:10.3390/ijerph182312319
62 David HS, Rosell T, Hughes D. Moral Injury Among Transplant Providers: Evaluating the Effects of Training in End-of-Life Counseling. Kansas journal of medicine. 2023;16(101581958):324–327. doi:10.17161/kjm.vol16.21171 38298384
63 Davies RL, Prince MA, Bravo AJ, Kelley ML, Crain TL. Moral Injury, Substance Use, and Posttraumatic Stress Disorder Symptoms Among Military Personnel: An Examination of Trait Mindfulness as a Moderator. Journal of traumatic stress. 2019;32(3):414–423. doi:10.1002/jts.22403 31141842
64 de la Rie SM, van Sint Fiet A, Bos JBA, Mooren N, Smid G, Gersons BPR. Brief Eclectic Psychotherapy for Moral Trauma (BEP-MT): treatment protocol description and a case study. European journal of psychotraumatology. 2021;12(1):1929026. doi:10.1080/20008198.2021.1929026 34262665
65 DeBeer BB, Mignogna J, Nance M, Bahraini N, Penzenik M, Brenner LA. COVID-19 and Lifetime Experiences of Trauma, Moral Injury, and Institutional Betrayal Among Healthcare Providers. Journal of occupational and environmental medicine. 2023;65(9):745–750. doi:10.1097/JOM.0000000000002891 37254232
66 DeCaro JB, Straka K, Malek N, Zalta AK. Sentenced to shame: Moral injury exposure in former lifers. Psychological trauma: theory, research, practice and policy. 2022;(101495376). doi:10.1037/tra0001400
67 Denham F, Varese F, Hurley M, Allsopp K. Exploring experiences of moral injury and distress among health care workers during the Covid-19 pandemic. Psychology and psychotherapy. 2023;96(4):833–848. doi:10.1111/papt.12471 37203424
68 Diekmann C, Issels L, Alliger-Horn C, Traumatized German soldiers with moral injury - value-based cognitive-behavioral group therapy to treat war-related shame. Frontiers in psychiatry. 2023;14(101545006):1173466. doi:10.3389/fpsyt.2023.1173466 37533887
69 Easterbrook B, Plouffe RA, Houle SA, Risk Factors for Moral Injury Among Canadian Armed Forces Personnel. Frontiers in psychiatry. 2022;13(101545006):892320. doi:10.3389/fpsyt.2022.892320 35633790
70 Easterbrook B, Plouffe RA, Houle SA, Moral injury associated with increased odds of past-year mental health disorders: a Canadian Armed Forces examination. European journal of psychotraumatology. 2023;14(1):2192622. doi:10.1080/20008066.2023.2192622 36994624
71 Espinola CW, Nguyen B, Torres A, Digital Interventions for Stress Among Frontline Health Care Workers: Results From a Pilot Feasibility Cohort Trial. JMIR serious games. 2024;12(101645255):e42813. doi:10.2196/42813 38194247
72 Eunyoung Jang. Mediating role of self-compassion in the association between moral injury and depression among Korean youths. Heliyon. 2022;8(5):e09429. doi:10.1016/j.heliyon.2022.e09429 35620628
73 Evans WR, Russell LH, Hall-Clark BN, Moral injury and moral healing in prolonged exposure for combat-related PTSD: A case study. Cognitive and Behavioral Practice. 2021;28(2):210–223. doi:10.1016/j.cbpra.2020.12.006
74 Evans WR, Stanley MA, Barrera TL, Exline JJ, Pargament KI, Teng EJ. Morally injurious events and psychological distress among veterans: Examining the mediating role of religious and spiritual struggles. Psychological trauma: theory, research, practice and policy. 2018;10(3):360–367. doi:10.1037/tra0000347 29154594
75 Fani N, Currier JM, Turner MD, Moral injury in civilians: associations with trauma exposure, PTSD, and suicide behavior. European journal of psychotraumatology. 2021;12(1):1965464. doi:10.1080/20008198.2021.1965464 34603635
76 Farrell D, Moran J, Zat Z, Group early intervention eye movement desensitization and reprocessing therapy as a video-conference psychotherapy with frontline/emergency workers in response to the COVID-19 pandemic in the treatment of post-traumatic stress disorder and moral injury-An. Frontiers in psychology. 2023;14(101550902):1129912. doi:10.3389/fpsyg.2023.1129912 37063579
77 Fatima M, Imran N, Aamer I, Iqtadar S, Shabbir B. When healers get wounded! Moral injury in healthcare providers during the COVID-19 pandemic in Pakistan. Frontiers in psychiatry. 2023;14(101545006):1244055. doi:10.3389/fpsyt.2023.1244055 37795516
78 Feingold D, Zerach G, Levi-Belz Y. The association between moral injury and substance use among Israeli combat veterans: The mediating role of distress and perceived social support. International Journal of Mental Health and Addiction. 2019;17(2):217–233. doi:10.1007/s11469-018-0012-8
79 Feinstein A, Pavisian B, Storm H. Journalists covering the refugee and migration crisis are affected by moral injury not PTSD. JRSM Open. 2018;9(3):205427041875901. doi:10.1177/2054270418759010
80 Fenton J, Kelly TB. “Risk is king and needs to take a backseat!” Can social workers’ experiences of moral injury strengthen practice? Journal of Social Work Practice. 2017;31(4):461–475. doi:10.1080/02650533.2017.1394827
81 Fernandez PE, Currier JM. Exploring the role of moral injury outcomes in intimate relationship functioning among U.S. combat veterans. Psychological trauma: theory, research, practice and policy. 2023;(101495376). doi:10.1037/tra0001553
82 Ferrajao PC, Oliveira RA. Self-awareness of mental states, self-integration of personal schemas, perceived social support, posttraumatic and depression levels, and moral injury: A mixed-method study among Portuguese war veterans. Traumatology. 2014;20(4):277–285. doi:10.1037/trm0000016
83 Finefter-Rosenbluh I. Behind the scenes of reflective practice in professional development: A glance into the ethical predicaments of secondary school teachers. Teaching and Teacher Education. 2016;60:1–11 doi:10.1016/j.tate.2016.07.028
84 Fino E, Daniels JK, Micheli G, Moral injury in a global health emergency: a validation study of the Italian version of the Moral Injury Events Scale adjusted to the healthcare setting. European journal of psychotraumatology. 2023;14(2):2263316. doi:10.1080/20008066.2023.2263316 37815082
85 Fischer IC, Norman SB, Feder A, Downstream consequences of moral distress in COVID-19 frontline healthcare workers: Longitudinal associations with moral injury-related guilt. General hospital psychiatry. 2022;79(fnk, 7905527):158–161. doi:10.1016/j.genhosppsych.2022.11.003 36403350
86 Fitzpatrick JJ, Pignatiello G, Kim M, Moral Injury, Nurse Well-being, and Resilience Among Nurses Practicing During the COVID-19 Pandemic. The Journal of nursing administration. 2022;52(7–8):392–398. doi:10.1097/NNA.0000000000001171 35815868
87 Forkus SR, Breines JG, Weiss NH. Morally injurious experiences and mental health: The moderating role of self-compassion. Psychological Trauma: Theory, Research, Practice, and Policy. 2019;11(6):630–638. doi:10.1037/tra0000446 30855154
88 Frankfurt SB, DeBeer BB, Morissette SB, Kimbrel NA, La Bash H, Meyer EC. Mechanisms of Moral Injury Following Military Sexual Trauma and Combat in Post-9/11 U.S. War Veterans. Frontiers in psychiatry. 2018;9(101545006):520. doi:10.3389/fpsyt.2018.00520 30450058
89 Frankfurt SB, Frazier P, Engdahl B. Indirect Relations Between Transgressive Acts and General Combat Exposure and Moral Injury. Military medicine. 2017;182(11):e1950–e1956. doi:10.7205/MILMED-D-17-00062 29087864
90 French L, Hanna P, Huckle C. “If I die, they do not care”: U.K. National Health Service staff experiences of betrayal-based moral injury during COVID-19. Psychological trauma: theory, research, practice and policy. 2022;14(3):516–521. doi:10.1037/tra0001134 34516222
91 Fulton T, Lathan EC, Karkare MC, Civilian Moral Injury and Amygdala Functional Connectivity During Attention to Threat. Biological psychiatry Cognitive neuroscience and neuroimaging. 2024;9(1):112–120. doi:10.1016/j.bpsc.2023.07.006 37487958
92 Gertler J, Dale L, Tracy N, Resilient, but for how long? The relationships between temperament, burnout, and mental health in healthcare workers during the Covid-19 pandemic. Frontiers in psychiatry. 2023;14(101545006):1163579. doi:10.3389/fpsyt.2023.1163579 37484670
93 Gibbons SW, Shafer M, Hickling EJ, Ramsey G. How do deployed health care providers experience moral injury?. Narrative inquiry in bioethics. 2013;3(3):247–259. doi:10.1353/nib.2013.0055 24407133
94 Gray MJ, Schorr Y, Nash W, Adaptive Disclosure: An Open Trial of a Novel Exposure-Based Intervention for Service Members With Combat-Related Psychological Stress Injuries. Behavior Therapy. 2012;43(2):407–415. doi:10.1016/j.beth.2011.09.001 22440075
95 Greene T, Harju-Seppanen J, Billings J, Brewin CR, Murphy D, Bloomfield MAP. Exposure to potentially morally injurious events in U.K. health and social care workers during COVID-19: Associations with PTSD and complex PTSD. Psychological trauma: theory, research, practice and policy. 2023;(101495376). doi:10.1037/tra0001519
96 Grimell J. Moral injury: understanding Swedish veterans who are assessed but not diagnosed with PTSD. Frontiers in psychiatry. 2023;14(101545006):1200869. doi:10.3389/fpsyt.2023.1200869 38111618
97 Guy C, Kunonga E, Kennedy A, Patel P. Moral injury and well-being in essential workers during the COVID-19 pandemic: local survey findings. BMJ leader. 2022;6(3):237–239. doi:10.1136/leader-2021-000518
98 Hagerty SL, Williams LM. Moral injury, traumatic stress, and threats to core human needs in health-care workers: The COVID-19 pandemic as a dehumanizing experience. Clinical Psychological Science. 2022;10(6):1060–1082. doi:10.1177/21677026211057554
99 Haight W, Cho M, Soffer-Elnekave R, Nashandi NJC, Suleiman J. Moral injury experienced by emerging adults with child welfare histories in developmental and sociocultural contexts: “I knew the system was broken”. Children and Youth Services Review. 2022;139:106537. doi:10.1016/j.childyouth.2022.106537
100 Haight W, Korang-Okrah R, Black JE, Gibson P, Nashandi NJC. Moral injury among Akan women: Lessons for culturally sensitive child welfare interventions. Children and Youth Services Review. 2020;110:104768 doi:10.1016/j.childyouth.2020.104768
101 Haight W, Sugrue E, Calhoun M, Black J. “Basically, I look at it like combat”: Reflections on moral injury by parents involved with child protection services. Children and Youth Services Review. 2017;82:477–489. doi:10.1016/j.childyouth.2017.10.009
102 Haight W, Sugrue E, Calhoun M, Black J. Everyday coping with moral injury: The perspectives of professionals and parents involved with child protection services. Children and Youth Services Review. 2017;82:108–121. doi:10.1016/j.childyouth.2017.09.025
103 Haight W, Sugrue EP, Calhoun M. Moral injury among Child Protection Professionals: Implications for the ethical treatment and retention of workers. Children and Youth Services Review. 2017;82:27–41. doi:10.1016/j.childyouth.2017.08.030
104 Hamrick HC, Ehlke SJ, Davies RL, Higgins JM, Naylor J, Kelley ML. Moral Injury as a Mediator of the Associations Between Sexual Harassment and Mental Health Symptoms and Substance Use Among Women Veterans. Journal of interpersonal violence. 2022;37(11–12):NP10007–NP10035. doi:10.1177/0886260520985485 33435809
105 Hamrick HC, Kelley ML, Bravo AJ. Morally Injurious Events, Moral Injury, and Suicidality among Recent-Era Veterans: The Moderating Effects of Rumination and Mindfulness. Military Behavioral Health. 2020;8(1):109–120. doi:10.1080/21635781.2019.1669509
106 Hanna P, Erickson M, Walker C. UK Higher Education staff experiences of moral injury during the COVID-19 pandemic. Higher education. 2022;(101726121):1–18. doi:10.1007/s10734-022-00956-z
107 Hansen KT, Nelson CG, Kirkwood K. Prevalence of Potentially Morally Injurious Events in Operationally Deployed Canadian Armed Forces Members. Journal of traumatic stress. 2021;34(4):764–772. doi:10.1002/jts.22710 34146353
108 Harris JI, Usset T, Cheng ZH. Theodicy and spiritual distress among veterans managing posttraumatic stress. Spirituality in Clinical Practice. 2018;5(4):240–250. doi:10.1037/scp0000170
109 He Z, Lei Q, Hu X, Moral injury and suicidal ideation among health professionals: The role of mental health. Journal of affective disorders. 2023;333(h3v, 7906073):58–64. doi:10.1016/j.jad.2023.04.033 37080491
110 Hegarty S, Lamb D, Stevelink SAM, “It hurts your heart”: frontline healthcare worker experiences of moral injury during the COVID-19 pandemic. European journal of psychotraumatology. 2022;13(2):2128028. doi:10.1080/20008066.2022.2128028 36276556
111 Held P, Klassen BJ, Hall JM, “I knew it was wrong the moment I got the order”: A narrative thematic analysis of moral injury in combat veterans. Psychological trauma: theory, research, practice and policy. 2019;11(4):396–405. doi:10.1037/tra0000364 29723032
112 Held P, Klassen BJ, Steigerwald VL, Do morally injurious experiences and index events negatively impact intensive PTSD treatment outcomes among combat veterans?. European journal of psychotraumatology. 2021;12(1):1877026. doi:10.1080/20008198.2021.1877026 34025919
113 Held P, Klassen BJ, Zou DS, Negative Posttrauma Cognitions Mediate the Association Between Morally Injurious Events and Trauma-Related Psychopathology in Treatment-Seeking Veterans. Journal of Traumatic Stress. 2017;30(6):698–703. doi:10.1002/jts.22234 29140560
114 Hendrikx LJ, Murphy D. Associations between International Trauma Questionnaire complex posttraumatic stress disorder symptom clusters and moral injury in a sample of U.K. treatment-seeking veterans: A network approach. Psychological trauma: theory, research, practice and policy. 2024;16(3):513–521. doi:10.1037/tra0001426 36701541
115 Hertz U, Snider KLG, Levy A, Canetti D, Gross ML. To shoot or not to shoot: experiments on moral injury in the context of West Bank checkpoints and COVID-19 restrictions enforcement. European journal of psychotraumatology. 2022;13(1):2013651. doi:10.1080/20008198.2021.2013651 35087644
116 Hines SE, Chin KH, Glick DR, Wickwire EM. Trends in Moral Injury, Distress, and Resilience Factors among Healthcare Workers at the Beginning of the COVID-19 Pandemic. International journal of environmental research and public health. 2021;18(2). doi:10.3390/ijerph18020488
117 Hines SE, Chin KH, Levine AR, Wickwire EM. Initiation of a survey of healthcare worker distress and moral injury at the onset of the COVID-19 surge. American journal of industrial medicine. 2020;63(9):830–833. doi:10.1002/ajim.23157 32677108
118 Hinkel HM, Currier JM, Isaak SL, McAdams E, Kilpatrick JF. Moral injury and chronic pain among military veterans in an integrated behavioral health clinic. Psychological trauma: theory, research, practice and policy. 2023;15(1):140–143. doi:10.1037/tra0001230 35324229
119 Hodgson TJ, Carey LB, Koenig HG. Moral Injury, Australian Veterans and the Role of Chaplains: An Exploratory Qualitative Study. Journal of religion and health. 2021;60(5):3061–3089. doi:10.1007/s10943-021-01417-0 34553273
120 Hodgson TJ, Carey LB, Koenig HG. Moral Injury, Betrayal and Retribution: Australian Veterans and the Role of Chaplains. Journal of religion and health. 2022;61(2):993–1021. doi:10.1007/s10943-022-01507-7 35175506
121 Hoffman J, Liddell B, Bryant RA, Nickerson A. The relationship between moral injury appraisals, trauma exposure, and mental health in refugees. Depression and anxiety. 2018;35(11):1030–1039. doi:10.1002/da.22787 30095203
122 Hoffman J, Liddell B, Bryant RA, Nickerson A. A latent profile analysis of moral injury appraisals in refugees. European journal of psychotraumatology. 2019;10(1):1686805. doi:10.1080/20008198.2019.1686805 31762953
123 Hoffman J, Nickerson A. The impact of moral-based appraisals on psychological outcomes in response to analogue trauma: An experimental paradigm of moral injury. Cognitive Therapy and Research. 2021;45(3):494–507. doi:10.1007/s10608-020-10172-7
124 Hoffman J, Nickerson A. An experimental investigation of the impact of blame appraisals and moral injury beliefs on psychological outcomes. Cognitive Therapy and Research. 2022;46(2):319–332. doi:10.1007/s10608-021-10264-y
125 Hoffman J, Nickerson A. The impact of moral-injury cognitions on psychological outcomes in refugees: An experimental investigation. Clinical Psychological Science. 2022;10(4):603–621. doi:10.1177/21677026211039516
126 Hollis J, Hanna P, Perman G. The shaping of moral injury among UK military veterans of the wars in Afghanistan and Iraq. Psychology and psychotherapy. 2023;96(1):209–222. doi:10.1111/papt.12434 36333240
127 Holtz HK, Weissinger GM, Swavely D, The Long Tail of COVID-19: Implications for the Future of Emergency Nursing. Journal of emergency nursing. 2023;49(2):198–209. doi:10.1016/j.jen.2022.10.006 36503829
128 Houle SA, Pollard C, Jetly R, Ashbaugh AR. Barriers and facilitators of help seeking among morally injured Canadian Armed Forces Veterans and service members: A qualitative analysis. Journal of Military, Veteran and Family Health. 2022;8(3):58–70. doi:10.3138/jmvfh-2021-0093
129 Houle SA, Vincent C, Jetly R, Ashbaugh AR. Patterns of distress associated with exposure to potentially morally injurious events among Canadian Armed Forces service members and Veterans: A multi-method analysis. Journal of clinical psychology. 2021;77(11):2668–2693. doi:10.1002/jclp.23205 34224575
130 Houtsma C, Khazem LR, Green BA, Anestis MD. Isolating effects of moral injury and low post-deployment support within the U.S. military. Psychiatry research. 2017;247(qc4, 7911385):194–199. doi:10.1016/j.psychres.2016.11.031 27918969
131 Jin J, Weiman K, Bremault-Phillips S, Vermetten E. Moral Injury and Recovery in Uniformed Professionals: Lessons From Conversations Among International Students and Experts. Frontiers in psychiatry. 2022;13(101545006):880442. doi:10.3389/fpsyt.2022.880442 35774092
132 Jinkerson JD, Battles AR. Relationships between moral injury syndrome model variables in combat veterans. Traumatology. 2019;25(1):33–40. doi:10.1037/trm0000163
133 Jordan AH, Eisen E, Bolton E, Nash WP, Litz BT. Distinguishing war-related PTSD resulting from perpetration- and betrayal-based morally injurious events. Psychological Trauma: Theory, Research, Practice, and Policy. 2017;9(6):627–634. doi:10.1037/tra0000249 28068142
134 Jovarauskaite L, Murphy D, Truskauskaite-Kuneviciene I, Dumarkaite A, Andersson G, Kazlauskas E. Associations between moral injury and ICD-11 post-traumatic stress disorder (PTSD) and complex PTSD among help-seeking nurses: a cross-sectional study. BMJ open. 2022;12(5):e056289. doi:10.1136/bmjopen-2021-056289
135 Kalmbach KC, Basinger ED, Bayles B, Moral injury in post-9/11 combat-experienced military veterans: A qualitative thematic analysis. Psychological services. 2023;(101214316). doi:10.1037/ser0000792
136 Kearney BE, Terpou BA, Densmore M, How the body remembers: Examining the default mode and sensorimotor networks during moral injury autobiographical memory retrieval in PTSD. NeuroImage Clinical. 2023;38(101597070):103426. doi:10.1016/j.nicl.2023.103426 37207593
137 Keenan MJ, Lamb T, Slattery M, Williams L, McMurtry M, Shakes D. Measuring moral injury and treatment response in justice-involved veterans: Development and validation of a new Moral Injury Scale. Traumatology. 2023;30(4):530–537 doi:10.1037/trm0000462
138 Kelley ML, Braitman AL, White TD, Ehlke SJ. Sex differences in mental health symptoms and substance use and their association with moral injury in veterans. Psychological trauma: theory, research, practice and policy. 2019;11(3):337–344. doi:10.1037/tra0000407 30234322
139 Kelley ML, Bravo AJ, Davies RL, Hamrick HC, Vinci C, Redman JC. Moral injury and suicidality among combat-wounded veterans: The moderating effects of social connectedness and self-compassion. Psychological trauma: theory, research, practice and policy. 2019;11(6):621–629. doi:10.1037/tra0000447 30896225
140 Kelley ML, Bravo AJ, Jinkerson JD, Ogle AD, Reichwald R, Rutland JB. Remote exposure to traumatic events and PTSD symptoms among U.S. Air Force intelligence personnel: Moderating effects of morally injurious experiences. Psychological trauma: theory, research, practice and policy. 2021;13(4):412–416. doi:10.1037/tra0000681 33539159
141 Kelley ML, Chae JW, Bravo AJ, Own soul’s warning: Moral injury, suicidal ideation, and meaning in life. Psychological trauma: theory, research, practice and policy. 2021;13(7):740–748. doi:10.1037/tra0001047 34351211
142 Kelley ML, Strowger M, Chentsova VO, Mindfulness to Manage Moral Injury: Rationale and development of a live online 7-week group intervention for veterans with moral injury. Contemporary clinical trials communications. 2022;30(101671157):101011. doi:10.1016/j.conctc.2022.101011 36340697
143 Khan AJ, Nishimi K, Tripp P, COVID-19 related moral injury: Associations with pandemic-related perceived threat and risky and protective behaviors. Journal of psychiatric research. 2021;142(jtj, 0376331):80–88. doi:10.1016/j.jpsychires.2021.07.037 34330024
144 King HA, Perry KR, Ferguson S, Identifying potentially morally injurious events from the Veteran perspective: A qualitative descriptive study. Journal of Military, Veteran and Family Health. 2023;9(2):27–39. doi:10.3138/jmvfh-2022-0049
145 King L, Ketcheson F, St Cyr K, Marlborough M, Richardson JD. Factor structure of deployment experiences and relations to mental health disorders among treatment-seeking Canadian armed forces personnel and veterans. Psychological trauma: theory, research, practice and policy. 2020;12(4):413–421. doi:10.1037/tra0000493 31318248
146 Kinney AR, Gerber HR, Hostetter TA, Brenner LA, Forster JE, Stephenson RO. Morally injurious combat events as an indirect risk factor for postconcussive symptoms among veterans: The mediating role of posttraumatic stress. Psychological trauma: theory, research, practice and policy. 2023;15(1):144–152. doi:10.1037/tra0001213 35084915
147 Knobloch LK, Owens JL. Moral injury among first responders: Experience, effects, and advice in their own words. Psychological services. 2024;(101214316). doi:10.1037/ser0000838
148 Koenig HG, Ames D, Youssef NA, Screening for Moral Injury: The Moral Injury Symptom Scale - Military Version Short Form. Military medicine. 2018;183(11–12):e659–e665. doi:10.1093/milmed/usy017 29590380
149 Koenig HG, Ames D, Youssef NA, The Moral Injury Symptom Scale-Military Version. Journal of religion and health. 2018;57(1):249–265. doi:10.1007/s10943-017-0531-9 29196962
150 Koenig HG, Youssef NA, Ames D, Moral Injury and Religiosity in US Veterans With Posttraumatic Stress Disorder Symptoms. The Journal of nervous and mental disease. 2018;206(5):325–331. doi:10.1097/NMD.0000000000000798 29494381
151 Koenig HG, Youssef NA, Ames D, Teng EJ, Hill TD. Examining the Overlap Between Moral Injury and PTSD in US Veterans and Active Duty Military. The Journal of nervous and mental disease. 2020;208(1):7–12. doi:10.1097/NMD.0000000000001077 31738222
152 Kok N, Zegers M, Fuchs M, van der Hoeven H, Hoedemaekers C, van Gurp J. Development of Moral Injury in ICU Professionals During the COVID-19 Pandemic: A Prospective Serial Interview Study. Critical care medicine. 2023;51(2):231–240. doi:10.1097/CCM.0000000000005766 36661451
153 Kopacz M, Bishop TM, Ayre A, Feasibility of using moral injury screening instruments in VA chaplaincy spiritual assessments. Journal of health care chaplaincy. 2022;28(sup1):S89–S100. doi:10.1080/08854726.2022.2032980 35130126
154 Kopacz MS, Adams MS, Searle R, Koenig HG, Bryan CJ. A Preliminary Study Examining the Prevalence and Perceived Intensity of Morally Injurious Events in a Veterans Affairs Chaplaincy Spiritual Injury Support Group. Journal of Health Care Chaplaincy. 2018;25(2):76–88. doi:10.1080/08854726.2018.1538655 30587079
155 Kovnick MO, Young Y, Tran N, Teerawichitchainan B, Tran TK, Korinek K. The Impact of Early Life War Exposure on Mental Health among Older Adults in Northern and Central Vietnam. Journal of health and social behavior. 2021;62(4):526–544. doi:10.1177/00221465211039239 34622692
156 Kreh A, Brancaleoni R, Magalini SC, Ethical and psychosocial considerations for hospital personnel in the Covid-19 crisis: Moral injury and resilience. PloS one. 2021;16(4):e0249609. doi:10.1371/journal.pone.0249609 33798251
157 Kvitsiani M, Mestvirishvili M, Martskvishvili K, Odilavadze M. Dynamic model of moral injury. European Journal of Trauma & Dissociation. 2023;7(1). doi:10.1016/j.ejtd.2023.100313
158 LaFrance WC, Vo P, Baird G, East R, Stein NR. Moral injury in Veterans with nonepileptic seizures. Epilepsy & Behavior. 2019;102:106681. doi:10.1016/j.yebeh.2019.106681 31766005
159 Lamb D, Gnanapragasam S, Greenberg N, Psychosocial impact of the COVID-19 pandemic on 4378 UK healthcare workers and ancillary staff: initial baseline data from a cohort study collected during the first wave of the pandemic. Occupational and environmental medicine. 2021;78(11):801–808. doi:10.1136/oemed-2020-107276 34183447
160 Lancaster SL, Irene Harris J. Measures of morally injurious experiences: A quantitative comparison. Psychiatry research. 2018;264(qc4, 7911385):15–19. doi:10.1016/j.psychres.2018.03.057 29626826
161 Lancaster SL, Miller M. Moral decision making, religious strain, and the experience of moral injury. Psychological trauma: theory, research, practice and policy. 2020;12(2):156–164. doi:10.1037/tra0000518 31566396
162 Lancaster SL. Negative outcomes after morally injurious experiences: A replication and extension. Psychological trauma: theory, research, practice and policy. 2018;10(4):456–462. doi:10.1037/tra0000341 29154599
163 Lathan EC, Powers A, Kottakis A, Civilian moral injury: associations with trauma type and high-frequency heart rate variability in two trauma-exposed community-based samples. Psychological medicine. 2023;53(11):5136–5145. doi:10.1017/S003329172200215X 37650341
164 Lathan EC, Sheikh IS, Guelfo A, Moral injury appraisals and dissociation: Associations in a sample of trauma-exposed community members. Journal of trauma & dissociation: the official journal of the International Society for the Study of Dissociation (ISSD). 2023;24(5):692–711. doi:10.1080/15299732.2023.2231010 37387238
165 Lee H, Aldwin CM, Kang S. Do different types of war stressors have independent relations with mental health? Findings from the Korean Vietnam Veterans Study. Psychological trauma: theory, research, practice and policy. 2022;14(5):840–848. doi:10.1037/tra0000557 32105130
166 Lei Q, He Z, Koenig HG, Light Personality Style and Moral Injury Among Chinese Health Professionals. Journal of religion and health. 2023;62(6):3942–3956. doi:10.1007/s10943-023-01921-5 37777659
167 Lennon RP, Parascando J, Talbot SG, Prevalence of Moral Injury, Burnout, Anxiety, and Depression in Healthcare Workers 2 Years in to the COVID-19 Pandemic. The Journal of nervous and mental disease. 2023;211(12):981–984. doi:10.1097/NMD.0000000000001705 38015191
168 Levi-Belz Y, Ben-Yehuda A, Levinstein Y, Zerach G. Moral injury and pre-deployment personality factors as contributors to psychiatric symptomatology among combatants: a two-year prospective study. European journal of psychotraumatology. 2024;15(1):2312773. doi:10.1080/20008066.2024.2312773 38334135
169 Levi-Belz Y, Ben-Yehuda A, Zerach G. Suicide risk among combatants: The longitudinal contributions of pre-enlistment characteristics, pre-deployment personality factors and moral injury. Journal of affective disorders. 2023;324(h3v, 7906073):624–631. doi:10.1016/j.jad.2022.12.160 36621681
170 Levi-Belz Y, Dichter N, Zerach G. Moral Injury and Suicide Ideation Among Israeli Combat Veterans: The Contribution of Self-Forgiveness and Perceived Social Support. Journal of interpersonal violence. 2022;37(1–2):NP1031–NP1057. doi:10.1177/0886260520920865 32410491
171 Levi-Belz Y, Greene T, Zerach G. Associations between moral injury, PTSD clusters, and depression among Israeli veterans: a network approach. European journal of psychotraumatology. 2020;11(1):1736411. doi:10.1080/20008198.2020.1736411 32313614
172 Levi-Belz Y, Groweiss Y, Blank C. Moral injury and its mental health consequences among protesters: findings from Israel’s civil protest against the government’s judicial reform. European journal of psychotraumatology. 2023;14(2):2283306. doi:10.1080/20008066.2023.2283306 37994789
173 Levi-Belz Y, Levinstein Y, Zerach G. The impact of moral injury on suicide risk among recently discharged Israeli veterans: A longitudinal moderated mediation model of trauma-related guilt and self-forgiveness. Psychological trauma: theory, research, practice and policy. 2024;(101495376). doi:10.1037/tra0001651
174 Levi-Belz Y, Shemesh S, Zerach G. Moral injury and suicide ideation among combat veterans: The moderating role of self-disclosure. Crisis: The Journal of Crisis Intervention and Suicide Prevention. 2023;44(3):198–208. doi:10.1027/0227-5910/a000849
175 Levi-Belz Y, Shemesh S, Zerach G. Moral Injury and Suicide Ideation Among Combat Veterans. Crisis. 2023;44(3):198–208. doi:10.1027/0227-5910/a000849 35138155
176 Levi-Belz Y, Zerach G. Moral injury, suicide ideation, and behavior among combat veterans: The mediating roles of entrapment and depression. Psychiatry research. 2018;269(qc4, 7911385):508–516. doi:10.1016/j.psychres.2018.08.105 30195745
177 Levi-Belz Y, Zerach G. The wounded helper: moral injury contributes to depression and anxiety among Israeli health and social care workers during the COVID-19 pandemic. Anxiety, stress, and coping. 2022;35(5):518–532. doi:10.1080/10615806.2022.2035371 35114876
178 Liang T, Kaka Mirza H, Malakoutikhah A, Moral Injury and its Correlates among Iranian Nurses in the Second Year of the COVID-19 Pandemic: A Multicenter Cross-Sectional Study. Journal of religion and health. 2023;62(6):3979–3994. doi:10.1007/s10943-023-01938-w 37864667
179 Litam SDA, Balkin RS. Moral injury in health-care workers during COVID-19 pandemic. Traumatology. 2021;27(1):14–19. doi:10.1037/trm0000290
180 Litz BT, Contractor AA, Rhodes C, Distinct Trauma Types in Military Service Members Seeking Treatment for Posttraumatic Stress Disorder. Journal of traumatic stress. 2018;31(2):286–295. doi:10.1002/jts.22276 29669185
181 Litz BT, Plouffe RA, Nazarov A, Defining and Assessing the Syndrome of Moral Injury: Initial Findings of the Moral Injury Outcome Scale Consortium. Frontiers in psychiatry. 2022;13(101545006):923928. doi:10.3389/fpsyt.2022.923928 35873252
182 Litz BT, Plouffe RA, Nazarov A, Defining and Assessing the Syndrome of Moral Injury: Initial Findings of the Moral Injury Outcome Scale Consortium. Front Psychiatry. 2022;13:923928. doi:10.3389/fpsyt.2022.923928 35873252
183 Litz BT, Rusowicz-Orazem L, Doros G, Adaptive disclosure, a combat-specific PTSD treatment, versus cognitive-processing therapy, in deployed marines and sailors: A randomized controlled non-inferiority trial. Psychiatry Research. 2021;297:113761. doi:10.1016/j.psychres.2021.113761 33540206
184 Liu G, Tong Y, Li J, Burnout, moral injury, and suicidal/self-harm ideation among healthcare professionals in Mainland China: Insights from an online survey during the COVID-19 pandemic. International journal of psychiatry in medicine. 2023;(0365646, gsj):912174231219041. doi:10.1177/00912174231219041
185 Lloyd CS, Nicholson AA, Densmore M, Shame on the brain: Neural correlates of moral injury event recall in posttraumatic stress disorder. Depression and anxiety. 2021;38(6):596–605. doi:10.1002/da.23128 33369799
186 LoSavio ST, Hale W, Straud CL, Impact of morally injurious traumatic event exposure on cognitive processing therapy outcomes among Veterans and service members. Journal of Military, Veteran and Family Health. 2023;9(2):40–51. doi:10.3138/jmvfh-2022-0048
187 Ma W, Koenig HG, Wen J, Liu J, Shi X, Wang Z. The moral injury, posttraumatic stress disorder, and suicidal behaviors in health professionals 1 year after the COVID-19 pandemic peak in China. Psychological Trauma: Theory, Research, Practice, and Policy. 2023;15(Suppl 2):S352–S356. doi:10.1037/tra0001483 38885427
188 Maguen S, Burkman K, Madden E, Impact of Killing in War: A Randomized, Controlled Pilot Trial: Impact of Killing in War. J Clin Psychol. 2017;73(9):997–1012. doi:10.1002/jclp.22471 28294318
189 Maguen S, Griffin BJ, Copeland LA, Perkins DF, Finley EP, Vogt D. Gender differences in prevalence and outcomes of exposure to potentially morally injurious events among post-9/11 veterans. Journal of psychiatric research. 2020;130(jtj, 0376331):97–103. doi:10.1016/j.jpsychires.2020.06.020 32805522
190 Maguen S, Griffin BJ, Copeland LA, Trajectories of functioning in a population-based sample of veterans: contributions of moral injury, PTSD, and depression. Psychological medicine. 2022;52(12):2332–2341. doi:10.1017/S0033291720004249 33234177
191 Maguen S, Griffin BJ, Vogt D, Moral injury and peri- and post-military suicide attempts among post-9/11 veterans. Psychological medicine. 2023;53(7):3200–3209. doi:10.1017/S0033291721005274 35034682
192 Maguen S, Nichter B, Norman SB, Pietrzak RH. Moral injury and substance use disorders among US combat veterans: results from the 2019–2020 National Health and Resilience in Veterans Study. Psychological medicine. 2023;53(4):1364–1370. doi:10.1017/S0033291721002919 34409932
193 Malakoutikhah A, Zakeri MA, Koenig HG, Dehghan M. The psychometric properties of the Persian version of the moral injury symptoms scale-health care professionals version. Frontiers in psychology. 2022;13(101550902):978572. doi:10.3389/fpsyg.2022.978572 35992473
194 Mantri S, Lawson JM, Wang Z, Koenig HG. Identifying Moral Injury in Healthcare Professionals: The Moral Injury Symptom Scale-HP. Journal of religion and health. 2020;59(5):2323–2340. doi:10.1007/s10943-020-01065-w 32681398
195 Mantri S, Lawson JM, Wang Z, Koenig HG. Prevalence and Predictors of Moral Injury Symptoms in Health Care Professionals. The Journal of nervous and mental disease. 2021;209(3):174–180. doi:10.1097/NMD.0000000000001277 33273393
196 Mantri S, Song YK, Lawson JM, Berger EJ, Koenig HG. Moral Injury and Burnout in Health Care Professionals During the COVID-19 Pandemic. The Journal of nervous and mental disease. 2021;209(10):720–726. doi:10.1097/NMD.0000000000001367 34582400
197 Martin RL, Houtsma C, Bryan AO, Bryan CJ, Green BA, Anestis MD. The impact of aggression on the relationship between betrayal and belongingness among U.S. military personnel. Military Psychology. 2017;29(4):271–282. doi:10.1037/mil0000160
198 McCormack L, Riley L. Medical discharge from the “family,” moral injury, and a diagnosis of PTSD: Is psychological growth possible in the aftermath of policing trauma? Traumatology. 2016;22(1):19–28. doi:10.1037/trm0000059
199 McDaniel JT, Redner R, Jayawardene W, Moral Injury is a Risk Factor for Substance Use and Suicidality Among US Military Veterans with and without Traumatic Brain Injury. Journal of religion and health. 2023;62(6):3926–3941. doi:10.1007/s10943-023-01905-5 37679519
200 McDaniel JT. Moral injury and quality of life among military veterans. BMJ military health. 2023;(101761581). doi:10.1136/military-2023-002457
201 McEwen C, Alisic E, Jobson L. Moral injury appraisals in young people from refugee backgrounds in Melbourne, Australia. Psychological trauma: theory, research, practice and policy. 2023;15(1):153–162. doi:10.1037/tra0001214 35201836
202 McGuire AP, Erickson TM, Nabulsi E. Assessing interpersonal impact of veterans with posttraumatic stress disorder and moral injury: A case study of how significant others perceive veterans undergoing a positive psychology intervention. Journal of Psychotherapy Integration. 2023;34(1):88–101. doi:10.1037/int0000317
203 McGuire AP, Howard BAN, Erickson TM, Creech SK. Moral Elevation Online Intervention for Veterans Experiencing Distress Related to Posttraumatic Stress Disorder and Moral Injury (MOVED): Pilot Trial of a 4-Week Positive Psychology Web-Based Intervention. JMIR formative research. 2023;7(101726394):e39894. doi:10.2196/39894 36961494
204 Mensink B, van Schagen A, van der Aa N, Ter Heide FJJ. Moral Injury in Trauma-Exposed, Treatment-Seeking Police Officers and Military Veterans: Latent Class Analysis. Frontiers in psychiatry. 2022;13(101545006):904659. doi:10.3389/fpsyt.2022.904659 35898627
205 Molendijk T. Moral injury in relation to public debates: The role of societal misrecognition in moral conflict-colored trauma among soldiers. Social science & medicine (1982). 2018;211(ut9, 8303205):314–320. doi:10.1016/j.socscimed.2018.06.042 29980118
206 Molendijk T. Toward an interdisciplinary conceptualization of moral injury: From unequivocal guilt and anger to moral conflict and disorientation. New Ideas in Psychology. 2018;51:1–8. doi:10.1016/j.newideapsych.2018.04.006
207 Mooren N, Boelen PA, de la Rie SM. The impact of morally injurious events in a refugee sample: A quantitative and qualitative study. Frontiers in psychiatry. 2022;13(101545006):904808. doi:10.3389/fpsyt.2022.904808 36159931
208 Morgan L, Beattie D, Irons C, Ononaiye M. The role of compassion in moral injury among military veterans: Implications for treatment. Psychological trauma: theory, research, practice and policy. 2024;(101495376). doi:10.1037/tra0001646
209 Morriss M, Berle D. Measuring moral injury: Further validation of the MIES-C and EMIS-C in a civilian population. Journal of Psychopathology and Behavioral Assessment. 2023;45(4):1046–1058. doi:10.1007/s10862-023-10071-7
210 Murphy D, Karatzias T, Busuttil W, Greenberg N, Shevlin M. ICD-11 posttraumatic stress disorder (PTSD) and complex PTSD (CPTSD) in treatment seeking veterans: risk factors and comorbidity. Social psychiatry and psychiatric epidemiology. 2021;56(7):1289–1298. doi:10.1007/s00127-021-02028-6 33464398
211 Murray E, Krahe C, Goodsman D. Are medical students in prehospital care at risk of moral injury?. Emergency medicine journal: EMJ. 2018;35(10):590–594. doi:10.1136/emermed-2017-207216 29945983
212 Nagdee N, Manuel de Andrade V. “I don’t really know where I stand because I don’t know if I took something away from her”: Moral injury in South African speech-language therapists and audiologists due to patient death and dying. International journal of language & communication disorders. 2023;58(1):28–38. doi:10.1111/1460-6984.12765 35925001
213 Nash WP, Marino Carper TL, Mills MA, Au T, Goldsmith A, Litz BT. Psychometric evaluation of the Moral Injury Events Scale. Military medicine. 2013;178(6):646–652. doi:10.7205/MILMED-D-13-00017 23756071
214 Nazarov A, Fikretoglu D, Liu A, Thompson M, Zamorski MA. Greater prevalence of post-traumatic stress disorder and depression in deployed Canadian Armed Forces personnel at risk for moral injury. Acta psychiatrica Scandinavica. 2018;137(4):342–354. doi:10.1111/acps.12866 29504125
215 Nazarov A, Fikretoglu D, Liu A, Richardson JD, Thompson M. Help-seeking for mental health issues in deployed Canadian Armed Forces personnel at risk for moral injury. European journal of psychotraumatology. 2020;11(1):1729032. doi:10.1080/20008198.2020.1729032 32194921
216 Nazarov A, Forchuk CA, Houle SA, Exposure to moral stressors and associated outcomes in healthcare workers: prevalence, correlates, and impact on job attrition. European journal of psychotraumatology. 2024;15(1):2306102. doi:10.1080/20008066.2024.2306102 38334695
217 Nelson KE, Hanson GC, Boyce D, Organizational Impact on Healthcare Workers’ Moral Injury During COVID-19: A Mixed-Methods Analysis. The Journal of nursing administration. 2022;52(1):57–66. doi:10.1097/NNA.0000000000001103 34910709
218 Ngo SB, Clark PJ, Parr SE, Moral Injury during the COVID-19 pandemic: A delphi model survey of family medicine residents. International journal of psychiatry in medicine. 2022;57(4):293–308. doi:10.1177/00912174211054385 34961337
219 Nguyen B, Torres A, Espinola CW, Development of a data-driven digital phenotype profile of distress experience of healthcare workers during COVID-19 pandemic. Computer Methods and Programs in Biomedicine. 2023;240:107645. doi:10.1016/j.cmpb.2023.107645 37352806
220 Nichter B, Norman SB, Maguen S, Pietrzak RH. Moral injury and suicidal behavior among US combat veterans: Results from the 2019–2020 National Health and Resilience in Veterans Study. Depression and anxiety. 2021;38(6):606–614. doi:10.1002/da.23145 33666315
221 Nickerson A, Byrow Y, Hoffman J, The longitudinal association between moral injury appraisals and psychological outcomes in refugees. Psychological medicine. 2022;52(12):2352–2364. doi:10.1017/S0033291720004262 33261693
222 Nickerson A, Hoffman J, Schick M, Schnyder U, Bryant RA, Morina N. A Longitudinal Investigation of Moral Injury Appraisals Amongst Treatment-Seeking Refugees. Frontiers in psychiatry. 2018;9(101545006):667. doi:10.3389/fpsyt.2018.00667 30618859
223 Nickerson A, Schnyder U, Bryant RA, Schick M, Mueller J, Morina N. Moral Injury in Traumatized Refugees. Psychotherapy and psychosomatics. 2015;84(2):122–123.25720427
224 Nieuwsma JA, Brancu M, Wortmann J, Smigelsky MA, King HA, Meador KG. Screening for moral injury and comparatively evaluating moral injury measures in relation to mental illness symptomatology and diagnosis. Clinical psychology & psychotherapy. 2021;28(1):239–250. doi:10.1002/cpp.2503 32830386
225 Nieuwsma JA, O’Brien EC, Xu H, Smigelsky MA, Meador KG. Patterns of Potential Moral Injury in Post-9/11 Combat Veterans and COVID-19 Healthcare Workers. Journal of general internal medicine. 2022;37(8):2033–2040. doi:10.1007/s11606-022-07487-4 35381899
226 Nillni YI, Shayani DR, Finley E, Copeland LA, Perkins DF, Vogt DS. The Impact of Posttraumatic Stress Disorder and Moral Injury on Women Veterans’ Perinatal Outcomes Following Separation From Military Service. Journal of traumatic stress. 2020;33(3):248–256. doi:10.1002/jts.22509 32291816
227 Norman SB, Griffin BJ, Pietrzak RH, McLean C, Hamblen JL, Maguen S. The Moral Injury and Distress Scale: Psychometric evaluation and initial validation in three high-risk populations. Psychological trauma: theory, research, practice and policy. 2024;16(2):280–291. doi:10.1037/tra0001533 37347882
228 Norman SB, Nichter B, Maguen S, Na PJ, Schnurr PP, Pietrzak RH. Moral injury among U.S. combat veterans with and without PTSD and depression. Journal of psychiatric research. 2022;154(jtj, 0376331):190–197. doi:10.1016/j.jpsychires.2022.07.033 35947898
229 Norman SB, Capone C, Panza KE, A clinical trial comparing trauma-informed guilt reduction therapy (TrIGR), a brief intervention for trauma-related guilt, to supportive care therapy. Depression and Anxiety. 2022;39(4):262–273. doi:10.1002/da.23244 35075738
230 Norman SB, Wilkins KC, Myers US, Allard CB. Trauma Informed Guilt Reduction Therapy With Combat Veterans. Cognitive and Behavioral Practice. 2014;21(1):78–88. doi:10.1016/j.cbpra.2013.08.001 25404850
231 O’Garo KGN, Koenig HG. Spiritually Integrated Cognitive Processing Therapy for Moral Injury in the Setting of PTSD: Initial Evidence of Therapeutic Efficacy. The Journal of nervous and mental disease. 2023;211(9):656–663. doi:10.1097/NMD.0000000000001686 37381149
232 O’Mathuna D, Smith J, Zadvinskis IM, Ethics and frontline nursing during COVID-19: A qualitative analysis. Nursing ethics. 2023;30(6):803–821. doi:10.1177/09697330221143150 36971185
233 Ogle AD, Reichwald R, Rutland JB. Psychological impact of remote combat/graphic media exposure among US Air Force intelligence personnel. Military Psychology. 2018;30(6):476–486. doi:10.1080/08995605.2018.1502999
234 Osmann J, Page-Gould E, Inbar Y, Dvorkin J, Walmsley D, Feinstein A. Validation of the Toronto Moral Injury Scale for Journalists. Traumatology. 2022;30(2):133. doi:10.1037/trm0000409
235 Paige L, Renshaw KD, Allen ES, Litz BT. Deployment trauma and seeking treatment for PTSD in US soldiers. Military Psychology. 2019;31(1):26–34. doi:10.1080/08995605.2018.1525219
236 Papazoglou K, Blumberg DM, Chiongbian VB, The Role of Moral Injury in PTSD Among Law Enforcement Officers: A Brief Report. Frontiers in psychology. 2020;11(101550902):310. doi:10.3389/fpsyg.2020.00310 32194477
237 Park S, Thrul J, Cooney EE, Betrayal-Based Moral Injury and Mental Health Problems Among Healthcare and Hospital Workers Serving COVID-19 Patients. Journal of trauma & dissociation: the official journal of the International Society for the Study of Dissociation (ISSD). 2023;(100898209):1–16. doi:10.1080/15299732.2023.2289195
238 Parry KJ, Hicken BL, Chen W, Leng J, Allen S, Burningham Z. Impact of moral injury and posttraumatic stress disorder on health care utilization and suicidality in rural and urban veterans. Journal of traumatic stress. 2023;36(1):117–128. doi:10.1002/jts.22889 36330588
239 Passardi S, Hocking DC, Morina N, Sundram S, Alisic E. Moral injury related to immigration detention on Nauru: a qualitative study. European journal of psychotraumatology. 2022;13(1):2029042. doi:10.1080/20008198.2022.2029042 35222839
240 Paul LA, Gros DF, Strachan M, Worsham G, Foa EB, Acierno R. Prolonged Exposure for Guilt and Shame in a Veteran of Operation Iraqi Freedom. American journal of psychotherapy. 2014;68(3):277–286.25505798
241 Peris J, Hanna P, Perman G. “It’s all very well for politicians in Whitehall to run a war, but they’re not on the ground”: U.K. military veterans’ experiences of betrayal-based moral injury. Traumatology. 2022;30(2):209. doi:10.1037/trm0000421
242 Pernicano PU, Wortmann J, Haynes K. Acceptance and forgiveness therapy for veterans with moral injury: spiritual and psychological collaboration in group treatment. Journal of health care chaplaincy. 2022;28(sup1):S57–S78. doi:10.1080/08854726.2022.2032982 35135436
243 Pfeffer C, Hart R, Satterthwaite M, Moral injury in human rights advocates. Psychological Trauma: Theory, Research, Practice, and Policy. 2023;15(Suppl 2):S268–S274. doi:10.1037/tra0001404 36455888
244 Phelps AJ, Madden K, Carleton RN, Towards a Holistic Model of Care for Moral Injury: An Australian and New Zealand Investigation into the Role of Police Chaplains in Supporting Police Members following exposure to Moral Transgression. Journal of religion and health. 2023;62(6):3995–4015. doi:10.1007/s10943-023-01908-2 37697218
245 Plouffe RA, Easterbrook B, Liu A, McKinnon MC, Richardson JD, Nazarov A. Psychometric Evaluation of the Moral Injury Events Scale in Two Canadian Armed Forces Samples. Assessment. 2023;30(1):111–123. doi:10.1177/10731911211044198 34515535
246 Presseau C, Litz BT, Kline NK, An epidemiological evaluation of trauma types in a cohort of deployed service members. Psychological trauma: theory, research, practice and policy. 2019;11(8):877–885. doi:10.1037/tra0000465 31070441
247 Protopopescu A, Boyd JE, O’Connor C, Examining the associations among moral injury, difficulties with emotion regulation, and symptoms of PTSD, depression, anxiety, and stress among Canadian military members and Veterans: A preliminary study. Journal of Military, Veteran and Family Health. 2021;7(2):71–80.
248 Purcell N, Burkman K, Keyser J, Fucella P, Maguen S. Healing from moral injury: A qualitative evaluation of the Impact of Killing treatment for combat veterans. Journal of Aggression, Maltreatment & Trauma. 2018;27(6):645–673. doi:10.1080/10926771.2018.1463582
249 Pyne JM, Rabalais A, Sullivan S. Mental Health Clinician and Community Clergy Collaboration to Address Moral Injury in Veterans and the Role of the Veterans Affairs Chaplain. Journal of health care chaplaincy. 2019;25(1):1–19. doi:10.1080/08854726.2018.1474997 30111274
250 Pyne JM, Sullivan S, Abraham TH, Rabalais A, Jaques M, Griffin B. Mental Health Clinician Community Clergy Collaboration to Address Moral Injury Symptoms: A Feasibility Study. Journal of religion and health. 2021;60(5):3034–3051. doi:10.1007/s10943-021-01257-y 33864575
251 Ranney RM, Maguen S, Bernhard PA, Moral injury and chronic pain in veterans. Journal of psychiatric research. 2022;155(jtj, 0376331):104–111. doi:10.1016/j.jpsychires.2022.08.009 36027646
252 Ray TN, Hunsanger JA, Nagy SM, Pickett SM. Potentially morally injurious events and depression symptoms among a trauma-exposed sample: Examining the roles of interpersonal needs and emotion dysregulation. Stress and health: journal of the International Society for the Investigation of Stress. 2021;37(1):151–161. doi:10.1002/smi.2981 32918366
253 Reynolds KA, Pankratz L, Jain B, Moral Injury Among Frontline Long-Term Care Staff and Management During the COVID-19 Pandemic. Frontiers in health services. 2022;2(9918334887706676):841244. doi:10.3389/frhs.2022.841244 36925899
254 Richardson CB, Chesnut RP, Morgan NR, Examining the Factor Structure of the Moral Injury Events Scale in a Veteran Sample. Military medicine. 2020;185(1–2):e75–e83. doi:10.1093/milmed/usz129 31184715
255 Richardson NM, Lamson AL, Hutto O. “My whole moral base and moral understanding was shattered”: A phenomenological understanding of key definitional constructs of moral injury. Traumatology. 2022;28(4):458–470. doi:10.1037/trm0000364
256 Ritchie K, D’Alessandro-Lowe AM, Brown A, The Hidden Crisis: Understanding Potentially Morally Injurious Events Experienced by Healthcare Providers during COVID-19 in Canada. IJERPH. 2023;20(6):4813. doi:10.3390/ijerph20064813 36981725
257 Rodrigues S, Mercier JM, McCall A, Nannarone M, Hosseiny F. “Against everything that got you into the job”: experiences of potentially morally injurious events among Canadian public safety personnel. European journal of psychotraumatology. 2023;14(2):2205332. doi:10.1080/20008066.2023.2205332 37170904
258 Rodriguez EA, Aguero-Flores M, Landa-Blanco M, Agurcia D, Santos-Midence C. Moral Injury and Light Triad Traits: Anxiety and Depression in Health-Care Personnel During the Coronavirus-2019 Pandemic in Honduras. Hispanic health care international: the official journal of the National Association of Hispanic Nurses. 2021;19(4):230–238. doi:10.1177/15404153211042371 34664509
259 Roth SL, Andrews K, Protopopescu A, Mental health symptoms in Public Safety Personnel: Examining the effects of adverse childhood experiences and moral injury. Child abuse & neglect. 2022;123(can, 7801702):105394. doi:10.1016/j.chiabu.2021.105394 34808481
260 Roth SL, Andrews K, Protopopescu A, Development and preliminary evaluation of the moral injury assessment for public safety personnel. Traumatology. 2023;29(2):301–308. doi:10.1037/trm0000367
261 Rushton CH, Thomas TA, Antonsdottir IM, Moral Injury and Moral Resilience in Health Care Workers during COVID-19 Pandemic. Journal of palliative medicine. 2022;25(5):712–719. doi:10.1089/jpm.2021.0076 34678091
262 Rushton CH, Nelson KE, Antonsdottir I, Hanson GC, Boyce D. Perceived organizational effectiveness, moral injury, and moral resilience among nurses during the COVID-19 pandemic: Secondary analysis. Nursing management. 2022;53(7):12–22. doi:10.1097/01.NUMA.0000834524.01865.cc
263 Russell B, Mussap AJ. Rumination and threat-biased interpretation mediate posttraumatic stress and growth responses to military stressors. Military psychology: the official journal of the Division of Military Psychology, American Psychological Association. 2023;35(5):451–466. doi:10.1080/08995605.2022.2127618 37615560
264 Saba SK, Davis JP, Lee DS, Castro CA, Pedersen ER. Moral injury events and behavioral health outcomes among American veterans. Journal of anxiety disorders. 2022;90(co1, 8710131):102605. doi:10.1016/j.janxdis.2022.102605 35868033
265 Schorr Y, Stein NR, Maguen S, Barnes JB, Bosch J, Litz BT. Sources of moral injury among war veterans: A qualitative evaluation. Journal of clinical psychology. 2018;74(12):2203–2218. doi:10.1002/jclp.22660 29984839
266 Schwartz G, Halperin E, Levi-Belz Y. Moral Injury and Suicide Ideation Among Combat Veterans: The Role of Trauma-Related Shame and Collective Hatred. Journal of interpersonal violence. 2022;37(15–16):NP13952–NP13977. doi:10.1177/08862605211007932 33858258
267 Sert-Ozen A, Kalaycioglu O. The Effect of Occupational Moral Injury on Career Abandonment Intention Among Physicians in the Context of the COVID-19 Pandemic. Safety and health at work. 2023;14(1):78–84. doi:10.1016/j.shaw.2022.12.002 36536655
268 Shapiro MO, Houtsma C, Schafer KM, True G, Miller L, Anestis M. Moral injury and suicidal ideation among female national guard members: Indirect effects of perceived burdensomeness and thwarted belongingness. Traumatology. 2022;30(2):231–237. doi:10.1037/trm0000424
269 Sharma ME, Cousins R. Understanding Moral Injury in Frontline Health Care Professionals 2 Years After the Onset of COVID-19. The Journal of nervous and mental disease. 2023;211(12):934–939. doi:10.1097/NMD.0000000000001665 37192009
270 Sherman M, Klinenberg E. Beyond burnout: Moral suffering among healthcare workers in the first COVID-19 surge. Social science & medicine (1982). 2024;340(ut9, 8303205):116471. doi:10.1016/j.socscimed.2023.116471 38061219
271 Simmons AM, Rivers FM, Gordon S, Yoder LH. The Role of Spirituality Among Military En Route Care Nurses: Source of Strength or Moral Injury?. Critical care nurse. 2018;38(2):61–67. doi:10.4037/ccn2018674 29606677
272 Singhal K, Chukkali S. Psychometric Properties of the Moral Injury Symptom Scale Among Indian Healthcare Professionals. Psychology research and behavior management. 2023;16(101514563):1439–1444. doi:10.2147/PRBM.S404094 37124074
273 Singhal K, Chukkali S. The role of guilt-shame proneness and locus of control in predicting moral injury among healthcare professionals. Cogent Psychology. 2023;10(1). doi:10.1080/23311908.2023.2264669
274 Smigelsky MA, Malott JD, Veazey Morris K, Berlin KS, Neimeyer RA. Latent profile analysis exploring potential moral injury and posttraumatic stress disorder among military veterans. Journal of clinical psychology. 2019;75(3):499–519. doi:10.1002/jclp.22714 30431152
275 Smigelsky MA, Malott J, Parker R, Check C, Rappaport B, Ward S. Let’s Get “REAL”: A Collaborative Group Therapy for Moral Injury. Journal of health care chaplaincy. 2022;28(sup1):S42–S56. doi:10.1080/08854726.2022.2032978 35112999
276 Smith-MacDonald L, Jones C, Brown MRG, Moving Forward from Moral Injury: A Mixed Methods Study Investigating the Use of 3MDR for Treatment-Resistant PTSD. International journal of environmental research and public health. 2023;20(7). doi:10.3390/ijerph20075415
277 Smith-MacDonald L, Lentz L, Malloy D, Bremault-Phillips S, Carleton RN. Meat in a Seat: A Grounded Theory Study Exploring Moral Injury in Canadian Public Safety Communicators, Firefighters, and Paramedics. International journal of environmental research and public health. 2021;18(22). doi:10.3390/ijerph182212145
278 Smith-MacDonald L, Lusk J, Lee-Baggley D, Companions in the Abyss: A Feasibility and Acceptability Study of an Online Therapy Group for Healthcare Providers Working During the COVID-19 Pandemic. Frontiers in psychiatry. 2021;12(101545006):801680. doi:10.3389/fpsyt.2021.801680 35115972
279 Soffer-Elnekave R, Haight W, Nashandi NJC, Cho M, Suleiman J, Park S. Re-orienting narratives of moral injury towards positive development: The experiences of emerging adults with child welfare histories. Children and Youth Services Review. 2023;149:106922. doi:10.1016/j.childyouth.2023.106922
280 Song YK, Mantri S, Lawson JM, Berger EJ, Koenig HG. Morally Injurious Experiences and Emotions of Health Care Professionals During the COVID-19 Pandemic Before Vaccine Availability. JAMA network open. 2021;4(11):e2136150. doi:10.1001/jamanetworkopen.2021.36150 34817579
281 Spaaij J, Schick M, Bryant RA, An exploratory study of embitterment in traumatized refugees. BMC psychology. 2021;9(1):96. doi:10.1186/s40359-021-00599-2 34112232
282 Stanojevic S, Cartolovni A. Moral distress and moral injury and their interplay as a challenge for leadership and management: The case of Croatia. Journal of nursing management. 2022;30(7):2335–2345. doi:10.1111/jonm.13835 36194206
283 Starnino VR, Sullivan WP, Angel CT, Davis LW. Moral injury, coherence, and spiritual repair. Mental Health, Religion & Culture. 2019;22(1):99–114. doi:10.1080/13674676.2019.1589439
284 Starnino VR, Sullivan WP, Angel CT, Davis LW. Like a Blanket Over a Fire: Group Work and Spiritual Repair in Military Trauma. Families in Society: The Journal of Contemporary Social Services. 2019;101(1):95–109. doi:10.1177/1044389419862081
285 Steen S, Morris D, Law GU, Fogarty L, Fox C. Assessing moral injury and its clinical associations in a U.K. secure care population. Traumatology. 2023;30(4):757–767. doi:10.1037/trm0000480
286 Stein NR, Mills MA, Arditte K, A scheme for categorizing traumatic military events. Behavior modification. 2012;36(6):787–807. doi:10.1177/0145445512446945 22679239
287 Steinmetz SE, Gray MJ, Clapp JD. Development and Evaluation of the Perpetration-Induced Distress Scale for Measuring Shame and Guilt in Civilian Populations. Journal of traumatic stress. 2019;32(3):437–447. doi:10.1002/jts.22377 30892734
288 Sullivan WP, Starnino VR. “Staring into the abyss”: Veterans’ accounts of moral injuries and spiritual challenges. Mental Health, Religion & Culture. 2019;22(1):25–40. doi:10.1080/13674676.2019.1578952
289 Sun D, Phillips RD, Mulready HL, Resting-State Brain Fluctuation and Functional Connectivity Dissociate Moral Injury from Posttraumatic Stress Disorder. bioRxiv. Published online 2018:442327. doi:10.1101/442327
290 Szabo D, Bekes V, Levay EE, Salgo E, Unoka ZS. Moral injury in psychiatric patients with personality and other clinical disorders: development, psychometric properties, and validity of the Moral Injury Events Scale-Civilian Version. European journal of psychotraumatology. 2023;14(2):2247227. doi:10.1080/20008066.2023.2247227 37650250
291 Tao H, Nieuwsma JA, Meador KG, Harris SL, Robinson PS. Validation of the Moral Injury Outcome Scale in acute care nurses. Frontiers in psychiatry. 2023;14(101545006):1279255. doi:10.3389/fpsyt.2023.1279255 38094593
292 Tappenden PC, Cole TA, Valentine JN, Lilly MM. Examining the psychometric properties of the expressions of moral injury scale in a sample of first responders. Psychological trauma: theory, research, practice and policy. 2023;(101495376). doi:10.1037/tra0001569
293 Tapson K, Doyle M, Karagiannopoulos V, Lee P. Understanding Moral Injury and Belief Change in the Experiences of Police Online Child Sex Crime Investigators: an Interpretative Phenomenological Analysis. Journal of police and criminal psychology. 2022;37(3):637–649. doi:10.1007/s11896-021-09463-w 34226793
294 Teng Y, Dehghan M, Hossini Rafsanjanipoor SM, Is nurses’ clinical competence associated with their moral identity and injury?. Nursing ethics. 2023;(b6m, 9433357):9697330231209284. doi:10.1177/09697330231209284
295 Terpou BA, Lloyd CS, Densmore M, Moral wounds run deep: exaggerated midbrain functional network connectivity across the default mode network in posttraumatic stress disorder. Journal of psychiatry & neuroscience: JPN. 2022;47(1):E56–E66. doi:10.1503/jpn.210117 35177485
296 Testoni I, Brondolo E, Ronconi L, Burnout following moral injury and dehumanization: A study of distress among Italian medical staff during the first COVID-19 pandemic period. Psychological trauma: theory, research, practice and policy. 2022;(101495376). doi:10.1037/tra0001346
297 Thomas ED, Weiss NH, Forkus SR, Contractor AA. Examining the Interaction Between Potentially Morally Injurious Events and Religiosity in Relation to Alcohol Misuse Among Military Veterans. Journal of traumatic stress. 2022;35(1):314–320. doi:10.1002/jts.22682 33964030
298 Thomas V, Bizumic B, Cruwys T, Walsh E. Measuring civilian moral injury: Adaptation and validation of the Moral Injury Events Scale (Civilian) and Expressions of Moral Injury Scale (Civilian). Psychological trauma: theory, research, practice and policy. 2024;16(2):270–279. doi:10.1037/tra0001490 37166915
299 Thomas V, Bizumic B, Quinn S. The Occupational Moral Injury Scale: Development and validation in frontline health and first responder workers. Traumatology. 2023;Advance online publication. doi:10.1037/trm0000482
300 Toyoda H, Ishikawa K, Omi Y, Kado T, Iizuka S, Endo T. Psychological violence victimization with moral injury in sports exacerbates PTSD symptoms. Sports Psychiatry: Journal of Sports and Exercise Psychiatry. 2023;2(1):3–12. doi:10.1024/2674-0052/a000034
301 Trifunovic-Koenig M, Strametz R, Gerber B, Mantri S, Bushuven S. Validation of the German Version of the Moral Injury Symptom and Support Scale for Health Professionals (G-MISS-HP) and Its Correlation to the Second Victim Phenomenon. International journal of environmental research and public health. 2022;19(8). doi:10.3390/ijerph19084857
302 Tripp JC, McDevitt-Murphy ME, Henschel AV. Firing a weapon and killing in combat are associated with suicidal ideation in OEF/OIF veterans. Psychological trauma: theory, research, practice and policy. 2016;8(5):626–633. doi:10.1037/tra0000085 26460495
303 Usset TJ, Gray E, Griffin BJ, Psychospiritual Developmental Risk Factors for Moral Injury. Religions. 2020;11(10):484. doi:10.3390/rel11100484
304 van Minnen A, Ter Heide FJJ, Koolstra T, de Jongh A, Karaoglu S, Gevers T. Initial development of perpetrator confrontation using deepfake technology in victims with sexual violence-related PTSD and moral injury. Frontiers in psychiatry. 2022;13(101545006):882957. doi:10.3389/fpsyt.2022.882957 36061287
305 Vargas AF, Hanson T, Kraus D, Drescher K, Foy D. Moral injury themes in combat veterans’ narrative responses from the National Vietnam Veterans’ Readjustment Study. Traumatology. 2013;19(3):243–250. doi:10.1177/1534765613476099
306 Volk F, Koenig HG. Moral Injury and Religiosity in Active Duty U.S. Military with PTSD Symptoms. Military Behavioral Health. 2019;7(1):64–72. doi:10.1080/21635781.2018.1436102
307 Wang Z, Al Zaben F, Koenig HG, Ding Y. Spirituality, moral injury and mental health among Chinese health professionals. BJPsych open. 2021;7(4):e135. doi:10.1192/bjo.2021.972 36043686
308 Wang Z, Koenig HG, Tong Y, Moral injury in Chinese health professionals during the COVID-19 pandemic. Psychological trauma: theory, research, practice and policy. 2022;14(2):250–257. doi:10.1037/tra0001026 34043381
309 Weber MC, Smith AJ, Jones RT, Moral injury and psychosocial functioning in health care workers during the COVID-19 pandemic. Psychological services. 2023;20(1):19–29. doi:10.1037/ser0000718
310 Wenzel D, Bleazard L, Wilson E, Faull C. Impact on staffof providing non-invasive advanced respiratory support during the COVID-19 pandemic: a qualitative study in an acute hospital. BMJ open. 2022;12(6):e060674. doi:10.1136/bmjopen-2021-060674
311 Whitehead PB, Haisch CE, Hankey MS, Studying moral distress (MD) and moral injury (MI) among inpatient and outpatient healthcare professionals during the COVID-19 pandemic. International journal of psychiatry in medicine. 2023;(0365646, gsj):912174231205660. doi:10.1177/00912174231205660
312 Williams CL, Berenbaum H. Acts of omission, altered worldviews, and psychological problems among military veterans. Psychological Trauma: Theory, Research, Practice, and Policy. 2019;11(4):391–395. doi:10.1037/tra0000394 30010380
313 Williamson C, Baumann J, Murphy D. Exploring the health and well-being of a national sample of U.K. treatment-seeking veterans. Psychological Trauma: Theory, Research, Practice, and Policy. 2023;15(4):672–680. doi:10.1037/tra0001356 36222665
314 Williamson V, Greenberg N, Murphy D. Impact of moral injury on the lives of UK military veterans: a pilot study. BMJ military health. 2020;166(5):302–306. doi:10.1136/jramc-2019-001243 31229989
315 Williamson V, Greenberg N, Murphy D. Moral injury in UK armed forces veterans: a qualitative study. European journal of psychotraumatology. 2019;10(1):1562842. doi:10.1080/20008198.2018.1562842 30693080
316 Williamson V, Greenberg N, Murphy D. Predictors of moral injury in UK treatment seeking veterans. Child abuse & neglect. 2021;112(can, 7801702):104889. doi:10.1016/j.chiabu.2020.104889 33360537
317 Williamson V, Lamb D, Hotopf M, Moral injury and psychological wellbeing in UK healthcare staff. Journal of mental health (Abingdon, England). 2023;32(5):890–898. doi:10.1080/09638237.2023.2182414 36883341
318 Williamson V, Murphy D, Stevelink SA, Jones E, Allen S, Greenberg N. Family and occupational functioning following military trauma exposure and moral injury. BMJ military health. 2023;169(3):205–211. doi:10.1136/bmjmilitary-2020-001770 33685904
319 Williamson V, Murphy D, Bonson A, Aldridge V, Serfioti D, Greenberg N. Restore and Rebuild (R&R) - a feasibility pilot study of a co-designed intervention for moral injury-related mental health difficulties. European journal of psychotraumatology. 2023;14(2):2256204. doi:10.1080/20008066.2023.2256204 37732994
320 Williamson V, Murphy D, Greenberg N. Experiences and impact of moral injury in U.K. veterinary professional wellbeing. European journal of psychotraumatology. 2022;13(1):2051351. doi:10.1080/20008198.2022.2051351 35432782
321 Williamson V, Murphy D, Greenberg N. Veterinary professionals’ experiences of moral injury: A qualitative study. The Veterinary record. 2023;192(2):e2181. doi:10.1002/vetr.2181 36065613
322 Williamson V, Murphy D, Stevelink SAM, Allen S, Jones E, Greenberg N. The impact of trauma exposure and moral injury on UK military veterans: a qualitative study. European journal of psychotraumatology. 2020;11(1):1704554. doi:10.1080/20008198.2019.1704554 32002137
323 Williamson V, Murphy D, Stevelink SAM, Allen S, Jones E, Greenberg N. The impact of moral injury on the wellbeing of UK military veterans. BMC psychology. 2021;9(1):73. doi:10.1186/s40359-021–00578-7 33952352
324 Wisco BE, Marx BP, May CL, Moral injury in U.S. combat veterans: Results from the national health and resilience in veterans study. Depression and anxiety. 2017;(csp, 9708816). doi:10.1002/da.22614
325 Woerner AJ, Greenberg CH, Chick JFB, Moral Injury Among Interventional Radiologists. Academic radiology. 2023;(clv, 9440159). doi:10.1016/j.acra.2023.09.015
326 Wong PH. Moral Injury in Former Child Soldiers in Liberia. Journal of child & adolescent trauma. 2022;15(3):847–856. doi:10.1007/s40653-021-00414-5 35958708
327 Youssef NA, Boswell E, Fiedler S, Moral injury, posttraumatic stress disorder, and religious involvement among U.S. veterans. Annals of clinical psychiatry: official journal of the American Academy of Clinical Psychiatrists. 2018;30(2):113–121.29697712
328 Youssef NA, Lee E, Ames D, Interest among veterans in spiritually-oriented therapy for inner conflict/moral injury in the setting of PTSD. Annals of clinical psychiatry: official journal of the American Academy of Clinical Psychiatrists. 2018;30(4):262–270.30372503
329 Zahiriharsini A, Gilbert-Ouimet M, Langlois L, Associations between psychosocial stressors at work and moral injury in frontline healthcare workers and leaders facing the COVID-19 pandemic in Quebec, Canada: A cross-sectional study. Journal of psychiatric research. 2022;155(jtj, 0376331):269–278. doi:10.1016/j.jpsychires.2022.09.006 36162193
330 Zasiekina L, Duchyminska T, Bifulco A, Bignardi G. War trauma impacts in Ukrainian combat and civilian populations: Moral injury and associated mental health symptoms. Military psychology: the official journal of the Division of Military Psychology, American Psychological Association. 2023;(8915802):1–12. doi:10.1080/08995605.2023.2235256
331 Zasiekina L, Zasiekin S, Kuperman V. Post-traumatic Stress Disorder and Moral Injury Among Ukrainian Civilians During the Ongoing War. Journal of community health. 2023;48(5):784–792. doi:10.1007/s10900-023-01225-5 37119352
332 Zefferman MR, Mathew S. An evolutionary theory of moral injury with insight from Turkana warriors. Evolution and Human Behavior. 2020;41(5):341–353. doi:10.1016/j.evolhumbehav.2020.07.003
333 Zerach G, Ben-Yehuda A, Levi-Belz Y. A prospective investigation of protective factors for moral injury and psychiatric symptomatology among Israeli combatants: A Latent Class Analysis approach. The International journal of social psychiatry. 2023;69(5):1134–1144. doi:10.1177/00207640231152211 36734242
334 Zerach G, Ben-Yehuda A, Levi-Belz Y. Pre-deployment aggressiveness, combat exposure and moral injury as contributors to posttraumatic stress symptoms among combatants: A two-year prospective study. Journal of psychiatric research. 2023;161(jtj, 0376331):158–164. doi:10.1016/j.jpsychires.2023.03.015 36931133
335 Zerach G, Ben-Yehuda A, Levi-Belz Y. Prospective associations between psychological factors, potentially morally injurious events, and psychiatric symptoms among Israeli combatants: The roles of ethical leadership and ethical preparation. Psychological trauma: theory, research, practice and policy. 2023;15(8):1367–1377. doi:10.1037/tra0001466 37011152
336 Zerach G, Levi-Belz Y. Moral injury process and its psychological consequences among Israeli combat veterans. Journal of clinical psychology. 2018;74(9):1526–1544. doi:10.1002/jclp.22598 29528102
337 Zerach G, Levi-Belz Y. Intolerance of Uncertainty Moderates the Association Between Potentially Morally Injurious Events and Suicide Ideation and Behavior Among Combat Veterans. Journal of traumatic stress. 2019;32(3):424–436. doi:10.1002/jts.22366 30720890
338 Zerach G, Levi-Belz Y. Moral injury and mental health outcomes among Israeli health and social care workers during the COVID-19 pandemic: a latent class analysis approach. European journal of psychotraumatology. 2021;12(1):1945749. doi:10.1080/20008198.2021.1945749 34367526
339 Zerach G, Levi-Belz Y. Exposure to combat incidents within military and civilian populations as possible correlates of potentially morally injurious events and moral injury outcomes among Israeli combat veterans. Clinical psychology & psychotherapy. 2022;29(1):274–288. doi:10.1002/cpp.2632 34128298
340 Zerach G, Levi-Belz Y. Moral injury, PTSD, and complex PTSD among Israeli health and social care workers during the COVID-19 pandemic: The moderating role of self-criticism. Psychological trauma: theory, research, practice and policy. 2022;14(8):1314–1323. doi:10.1037/tra0001210 35099215
341 Zerach G, Levi-Belz Y. Exposure to potentially morally injurious events, disruption in assumptive world, moral injury symptoms, and psychological distress among Israeli female veterans. Stress and health: journal of the International Society for the Investigation of Stress. 2023;39(3):651–662. doi:10.1002/smi.3214 36525571
342 Zerach G, Levi-Belz Y, Griffin BJ, Maguen S. Patterns of exposure to potentially morally injurious events among Israeli combat veterans: A latent class analysis approach. Journal of anxiety disorders. 2021;79(co1, 8710131):102378. doi:10.1016/j.janxdis.2021.102378 33647608
343 Zhizhong W, Koenig HG, Yan T, Psychometric properties of the moral injury symptom scale among Chinese health professionals during the COVID-19 pandemic. BMC psychiatry. 2020;20(1):556. doi:10.1186/s12888-020-02954-w 33238949

## CHARACTERISTICS OF INCLUDED STUDIES FOR KQ2

Study; Secondary Publications | Sample Size | Population^a^ | % Post-9/11 | % Deployed | Exposure Detail; MI/PMIE Measure | Associations
Battles 2019; Battles 2018; Braitman 2018; Davies 2019; Hamrick 2020 | N=380 | Veterans and ADSMs; Mean age: 35; % male: 68; % Black: NR; % White: 69; % Hispanic/Latinx: NR | 100 | 100 | PMIE exposure and MI symptoms; MIQ-M | PTSD symptoms, depressive symptoms, anxiety symptoms, suicidality, drug use, total alcohol use, alcohol consumption, alcohol dependence, alcohol problems
Boscarino 2022 | N=1032 | Veteran outpatients; Mean age: 62; % male: 95; % Black: NR; % White: NR; % Hispanic/Latinx: NR | NR | 100 | MI^b^; MIES | Alcohol dependence, opioid use disorder, lifetime marijuana use
Bravo 2020; Kelley 2019 | N=189 | Combat-wounded Veterans; Mean age: 43; % male: 97; % Black: NR; % White: 74; % Hispanic/Latinx: NR | 86 | 100 | MI; EMIS-M | Depression symptoms, anxiety symptoms, suicidality, PTSD symptoms
Bryan 2014; Bryan 2016 Study 1 | N=151 | ADSM outpatients; Mean age: 34; % male: 64; % Black: 21; % White: 68; % Hispanic/Latinx: 10 | 100 | 57 | MI; MIES | PTSD symptoms, depression symptoms, current suicide ideation
Bryan 2016 Study 2 | N=1086 | ADSMs; Mean age: 34; % male: 64; % Black: 21; % White: 67; % Hispanic/Latinx: NR | 100 | 67 | PMIE exposure; MIES | PTSD symptoms, depression symptoms
Bryan 2018 | N=930 | ADSMs; Mean age: NR; % male: 87; % Black: 2; % White: 89; % Hispanic/Latinx: 7 | 100 | 58 | MI symptoms sorrow, regret, shame, alienation; Items from DES-IV; DRRI-2 | Suicide ideation, suicide attempts, PTSD symptoms
Cameron 2021 | N=40 | Veteran inpatients with SUD and suicidal ideation; Mean age: 48; % male: 92; % Black: 13; % White: 79; % Hispanic/Latinx: NR | NR | NR | MIE exposure; MIES | Depression symptoms, suicide ideation, PTSD diagnosis
Currier 2015 Currier 2015 | N=131 | Veterans; Mean age: 28; % male: 88; % Black: 16; % White: 26; % Hispanic/Latinx: 42 | 100 | 100 | MIEs; MIQ-M | PTSD symptoms, depression, suicide risk
Currier 2018 Study 1; Currier 2019 | N=286 | Veterans endorsing MI; Mean age: NR; % female: 32; % Black: 16; % White: 68; % Hispanic/Latinx: 5 | NR | 100 | Expression of MI; EMIS-M | PTSD symptoms, depression symptoms, alcohol misuse
Currier 2018 Study 2; Currier 2020 Study 1 | N=624 | Veterans; Mean age: NR; % female: 19; % Black: 11; % White: 80; % Hispanic/Latinx: 7 | NR | 100 | Expression of MI; EMIS-M | PTSD symptoms, depression symptoms, alcohol misuse
Currier 2020 Study 2 | N=316 | Veterans; Mean age: NR; % female: 25; % Black: 19; % White: 70; % Hispanic/Latinx: 17 | 100 | 100 | MI expression; EMIS-M; EMIS-M-SF | PTSD symptoms
Evans 2018 | N=155 | Veteran outpatients with religion/spirituality struggles; Mean age: 51; % male: 86; % Black: 60; % White: 26; % Hispanic/Latinx: 12 | 23 | 55 | PMIE exposure; MIES | PTSD symptoms, depression symptoms, anxiety symptoms
Fernandez 2023 | N=65 | Veteran outpatients; Mean age: 46; % male: 92; % Black: 8; % White: 66; % Hispanic/Latinx: 22 | NR | 100 | MI outcomes; EMIS-M | PTSD symptoms, intimate relationship functioning
Forkus 2019 | N=203 | Veterans; Mean age: 35; % male: 77; % Black: NR; % White: 70; % Hispanic/Latinx: NR | NR | 100 | PMIE exposure; MIES | PTSD, depression, alcohol misuse, drug misuse
Frankfurt 2017 | N=65 | Veteran outpatients; Mean age: 55; % male: 100; % Black: 1; % White: 96; % Hispanic/Latinx: NR | 31 | 100 | Transgressive acts; None ^c^ | PTSD symptoms, suicidality
Frankfurt 2018 | N=310 | Veteran outpatients; Mean age: 41; % male: 76; % Black: 32; % White: 96; % Hispanic/Latinx: 19 | 100 | NR^d^ | Exposure to betrayal or perpetration; MIES | Depression symptoms, PTSD symptoms
Hamrick 2022 | N=154 | Veterans and ADSMs; Mean age: 37; % male: 0; % Black: 9; % White: 72; % Hispanic/Latinx: 16 | NR | NR | Other-directed MI; EMIS-M | Depression, anxiety, suicidal ideation, and substance use
Held 2017 | N=121 | Veteran outpatients with PTSD; Mean age: 39; % male: 66; % Black: NR; % White: 67; % Hispanic/Latinx: 25 | 88.4 | NR | PMIE exposure; MIES | PTSD symptoms, depression symptoms
Held 2021 | N=161 | Veterans and ADSM outpatients with PTSD; Mean age: 40; % male: 91; % Black: 16; % White: 71; % Hispanic/Latinx: 22 | 96 | NR | PMIE exposure; MIES | PTSD symptoms, depression symptoms
Jinkerson 2019 | N=72 | Veterans; Mean age: NR^e^; % male: 88; % Black: 47; % White: 46; % Hispanic/Latinx: 22 | NR | 100 | PMIE exposure; MIQ-M | Depression symptoms, anxiety symptoms, PTSD symptoms
Jordan 2017; Nash 2013 | N=867 | ADSMs; Mean age: NR; % male: NR; % Black: NR; % White: NR; % Hispanic/Latinx: NR | 100 | NR | PMIE exposure; MIES | PTSD symptoms, depression symptoms, anxiety symptoms
Keenan 2023 | N=180 | Justice-involved Veterans; Mean age: 36; % male: 93; % Black: 17; % White: 57; % Hispanic/Latinx: 21 | NR | NR | MI; MIS | PTSD symptoms
Kelley 2019 | N=256 | Veterans and ADSMs; Mean age: 33; % male: 61; % Black: NR; % White: 68; % Hispanic/Latinx: NR | 100 | 100 | MIE exposure and MI; MIQ-M | PTSD symptoms, depression symptoms, anxiety symptoms, suicidality, hazardous alcohol use, drug abuse
Kelley 2021 (own soul’s warning) | N=269 | Veterans and ADSMs; Mean age: 37; % male: 50; % Black: 10; % White: 74; % Hispanic/Latinx: 12 | NR | 100 | MI; EMIS-M | Suicidal ideation, PTSD diagnosis
Kelley 2021 | N=277 | USAF ISR personnel who experienced graphic work-related media exposure; Mean age: NR; % male: 72; % Black: NR; % White: NR; % Hispanic/Latinx: NR | 100 | NR | PMIE exposure; MIES | PTSD symptoms
Kinney 2023 | N=145 | Veteran outpatients with mTBI; Mean age: 33; % male: 92; % Black: NR; % White: NR; % Hispanic/Latinx: NR | 100 | 100 | PMIE exposure; MIES | PTSD symptoms
Koenig 2020; Koenig 2018; Koenig 2018; Koenig 2018; Ames 2018; Volk 2019 | N=591 | Veterans and ADSMs with PTSD symptoms; Mean age: 51; % male: 86; % Black: 44; % White: 41; % Hispanic/Latinx: NR | NR | 100 | MI symptoms; MISS-M; MISS-M-SF | PTSD symptoms, PTSD diagnosis, depression symptoms, anxiety symptoms, current use of alcohol, relationship quality, involvement in community activities, physical disability, suicide risk
LaFrance 2019 | N=82 | Veteran outpatients with psychogenic nonepileptic seizures; Mean age: NR; % male: 79; % Black: NR; % White: NR; % Hispanic/Latinx: NR | NR | NR | PMIE exposure; None ^f^ | PTSD diagnosis, mood disorder diagnosis, current substance abuse, suicide ideation, depression symptoms
Lancaster 2018 | N=161 | Veterans and ADSMs; Mean age: 35; % male: 71; % Black: 12; % White: 74; % Hispanic/Latinx: 5 | 100 | 100 | PMIE exposure; MIES ^g^ | PTSD symptoms, depression symptoms
Lancaster 2018 (measures) | N=182 | Veterans; Mean age: 34; % male: 80; % Black: 9; % White: 78; % Hispanic/Latinx: 8 | 100 | 100 | PMIE exposure; MIES; MIQ-M | PTSD symptoms, depression symptoms, hazardous alcohol use
Litz 2018 | N=999 | ADSMs who experienced a Criterion A event; Mean age: 33; % male: 91; % Black: 25; % White: 56; % Hispanic/Latinx: 20 | 100 | 100 | PMIE exposure; None ^h^ | PTSD symptoms
Maguen 2020; Chesnut 2020; Nillni 2020; Maguen 2022 | N=7200 | Veterans; Mean age: 34; % male: 82; % Black: NR; % White: 66; % Hispanic/Latinx: NR | 100 | 71 | PMIE exposure; MIES | PTSD, depression, anxiety, hazardous drinking, impaired work functioning, impaired educational functioning, impaired financial functioning, impaired health functioning, impaired relationship functioning, impaired parental functioning, impaired broad social functioning, postpartum depression/anxiety
Maguen 2023 | N=14057 | Veterans; Mean age: NR; % male: 82; % Black: 13; % White: 66; % Hispanic/Latinx: 11 | 100 | 57 | Exposure to and subjective distress stemming from PMIEs; MIES | Suicidal self-directed violence
McDaniel 2023 | N=1487 | Veterans; Mean age: 50; % male: 68; % Black: 15; % White: 76; % Hispanic/Latinx: NR | NR | NR | MI; MISS-M-SF | Substance use, suicide risk
Nichter 2021; Norman 2022; Maguen 2023 | N=1321 | Veterans; Mean age: 59; % male: 94; % Black: 12; % White: 75; % Hispanic/Latinx: 8 | 33 | 100 | PMIE exposure; MIES | Current suicide ideation, lifetime suicide plans, lifetime suicide attempts, past-year and lifetime AUD, DUD, SUD, probable PTSD or subthreshold PTSD, probable depression
Nieuwsma 2022; Nieuwsma 2021 | N=618 | Veterans; Mean age: 47; % male: 84; % Black: 41; % White: 51; % Hispanic/Latinx: 5 | 100 | 100 | PMIE exposure and ongoing sequela; MIES, MIQ-M, BMIS | PTSD symptoms, depression symptoms, suicidality, hazardous alcohol use, drug abuse
Ogle 2018 | N=356 | USAF ISR personnel with MI symptoms; Mean age: NR; % male: 70; % Black: NR; % White: NR; % Hispanic/Latinx: NR | 100 | 17 | MI symptoms; MIES | PTSD symptoms
Paige 2019; Bhalla 2018 | N=600 | Veterans and ADSMs; Mean age: 31; % male: 100; % Black: 7; % White: 76; % Hispanic/Latinx: 11 | 100 | 100 | Frequency of PMIEs; PMIE exposure; MIES; None ^i^ | PTSD symptoms, sexual anxiety
Parry 2023 | N=1545 | Veteran outpatients; Mean age: 46; % male: 70; % Black: NR; % White: NR; % Hispanic/Latinx: NR | NR | NR | MI; MIES | Suicidality
Presseau 2019 | N=789 | ADSMs; Mean age: 27; % male: 89; % Black: NR; % White: 64; % Hispanic/Latinx: 21 | 100 | 100 | Criterion A trauma type categorized as MI-self or MI-other; SCID | PTSD symptoms, PTSD symptom burden, hazardous alcohol use, anxiety symptoms, depression symptoms, suicidality
Richardson 2022 | N=62 | Veterans; Mean age: NR; % male: NR; % Black: NR; % White: NR; % Hispanic/Latinx: NR | NR | NR | PMIE exposure and association symptoms; MIES; MISS-M | PTSD, depression symptoms, history of suicidal ideation
Saba 2022 | N=1005 | Veterans; Mean age: 35; % male: 91; % Black: 5; % White: 85; % Hispanic/Latinx: 9 | 100 | NR | PMIE exposure; MIES | PTSD symptoms, depression symptoms, anxiety symptoms
Shapiro 2022 | N=151 | ADSMs; Mean age: 28; % male: 0; % Black: 49; % White: 42; % Hispanic/Latinx: 4 | 100 | 60 | PMIE exposure; MIES | Suicidal ideation
Stein 2012 | N=127 | ADSM outpatients with PTSD symptoms; Mean age: NR; % male: NR; % Black: NR; % White: NR; % Hispanic/Latinx: NR | NR | NR | PMIE exposure; None ^j^ | PTSD symptoms
Thomas 2022 | N=496 | Veterans; Mean age: 38; % male: 71; % Black: 22; % White: 71; % Hispanic/Latinx: 23 | NR | NR | PMIE exposure; MIES | Hazardous alcohol use
Tripp 2016 | N=68 | Veteran outpatients with hazardous alcohol use; Mean age: 32; % male: 91; % Black: 28; % White: 65; % Hispanic/Latinx: NR | 100 | 100 | Firing a weapon/killing in combat (Firing/Killing) and killing in combat (Killing) alone; None | PTSD symptoms, depression symptoms, suicide ideation
Usset 2019 | N=212 | Veterans receiving VA PTSD care; Mean age: 58; % male: 81; % Black: 5; % White: 88; % Hispanic/Latinx: 2 | 100 | 100 | PMIE exposure; MIES; MIQ-M | PTSD symptoms
Williams 2019 | N=50 | Veterans; Mean age: 33; % female: 8; % Black: 22; % White: 71; % Hispanic/Latinx: 23 | 100 | 100 | Exposure to acts of commission and omission; MIES | PTSD symptoms, depression symptoms, suicidality, alcohol use
Wisco 2017; Corona 2019 | N=564 | Veterans; Mean age: NR^k^; % female: 7; % Black: 6; % White: 74; % Hispanic/Latinx: 8 | NR | 100 | PMIE exposure; MIES | Current mental disorder (depression, anxiety, PTSD), suicidal ideation, suicide attempts
Youssef 2018 | N=120 | Veteran outpatients with PTSD symptoms and/or symptoms of inner conflict; Mean age: 57; % male: 86; % Black: 63; % White: 30; % Hispanic/Latinx: NR | NR | 100 | MI symptoms; MISS | PTSD symptoms

Notes.

a ADSMs may include National Guard/Reserve members

b Dichotomized into low or high

c Trauma narratives were coded for 8 transgressive acts

d 99% with combat exposure

e 89% 36 years or older

f Identified by chart review

g Also used ad hoc items to assess exposure to transgressive acts

h Moral injury-self and moral injury-other were Criterion A event types

i Assessed frequency of traumatic incidents including moral injury-self and moral injury-other

j Developed scheme to categorize index events, including MI-Self and MI-Other

k 58.5% 60 years or older.

Abbreviations. ADSMs=active-duty service members; AUD=alcohol use disorder; BMIS=Brief Moral Injury Screen; DES-IV=Differential Emotions Scale; DRRI-2=Deployment Risk and Resilience Inventory; DUD=drug use disorder; EMIS-M; Expressions of Moral Injury Scale - Military; ISR=intelligence, surveillance, and reconnaissance; MI=moral injury; MIE=moral injury exposure; MIES=Moral Injury Events Scale; MIQ-M=Moral Injury Questionnaire – Military; MIS=Moral Injury Scale; MISS-M=Moral Injury Symptom Scale – Military; MISS-M-SF=Moral Injury Symptom Scale – Military – short form; mTBI=mild traumatic brain injury; NR=not reported; PMIE=potentially morally injurious experience; SCID=Structured Clinical Interview for DSM-V; SUD=substance use disorder; USAF=US Air Force.

## RISK OF BIAS ASSESSMENTS

### OBSERVATIONAL STUDIES (QUIPS)

Author Year | Study Participation | Study Attrition | Prognostic Factor Measurement | Outcome Measurement | Study Confounding | Statistical Analysis and Reporting | Overall Risk of Bias
Battles 2019; Battles 2018; Braitman 2018; Davies 2019; Hamrick 2020 | Moderate; Potential participants were identified from a university setting (86% students). Participants were volunteers. % race/ethnicity other than White not reported. | Low; Cross-sectional study. No attrition reported. | Moderate; Modified MIQ-M (12/20 items were included) was used to assess PMIE exposure for all participants. Little missing data on MIQ-M items (0.3%). Maximum likelihood estimation used to address data which were determined to be missing at random. | Low; Mental health correlates assessed with validated measures in the same manner for all participants. | Moderate; Adjusted for gender, military status, years in the military, and branch of service. Other potential confounders not considered. | Low; Analyses were appropriate and no evidence of selective reporting. | Moderate
Boscarino 2022 | Moderate; Random sample of Veteran outpatients selected from a registry of patients of a private clinic. 55% of eligible Veterans completed the study. Responders tended to be younger and more often married. | Moderate; Survey was conducted across 2 time points, and it is unclear whether attrition occurred. Appears to only include participants who completed the 2nd survey. | Moderate; MIES was used to assess MI for all participants. No information on missing data. | Low; Mental health correlates assessed with validated measures in the same manner for all participants. | Moderate; Control variables included age, gender, race, warzone deployments, being drafted, concussion history, Guard/Reserve status, and combat exposure. Other potential confounders not considered. | Moderate; Do not describe how missing data were addressed. Report indicates that some results are available from the authors upon request | Moderate
Bravo 2020; Kelley 2019 | Moderate; Potential participants were members of the Combat Wounded Coalition. An email was sent inviting members to participate (8.5% participation rate after excluding individuals without deployment). | Low; Cross-sectional study. No attrition reported. | Moderate; EMIS-M was used to assess MI in the same manner for all participants. No information on degree or handling of missing data. | Low; Mental health correlates assessed with validated measures in the same manner for all participants. | Moderate; Years served in the military and number of deployments (in months) were modeled as predictors. Other potential confounders not accounted for. | Moderate; Do not describe how missing data were addressed. No evidence of selective reporting. | Moderate
Bryan 2014; Bryan 2016 Study 1 | Moderate; Recruited from outpatient clinics. Unclear whether participants were approached consecutively for participation. | Low; Cross-sectional study. No attrition reported. | Moderate; MIES was used to assess MI for all participants. No information on missing data. | Low; Mental health correlates assessed with validated measures in the same manner for all participants. | Moderate; Gender, age, posttraumatic stress symptoms, depression, and hopelessness included as covariates. Other potential confounders not considered. | Moderate; Do not describe how missing data were addressed. No evidence of selective reporting. | Moderate
Bryan 2016 Study 2 | Moderate; Soldiers recruited from training. Unclear how many eligible individuals declined participation. | Moderate; Data were missing for 27% of training camp participants due to competing demands of training. | Low; MIES was used to assess PMIE exposure for all participants. No information on missing data for this measure, but MLE was used to account for missing data. | Low; Mental health correlates assessed with validated measures in the same manner for all participants. | High; Analyses did not account for potential confounders. | Low; Analyses were appropriate and no evidence of selective reporting. | Moderate
Bryan 2018 | Low; Address to online survey was distributed to National Guard personnel. Do not report how many eligible individuals did not participate. Data were weighted to address gender and age discrepancies between sample and overall population. | Low; Cross-sectional study. No attrition reported. | High; Assessed the MI symptoms of sorrow, regret, shame, and alienation with items from 2 non-MI scales. Assessment was the same for all participants. Do not report extent of missing data. | Low; Mental health correlates assessed with validated measures in the same manner for all participants. | High; Relevant analyses do not account for potential confounders. | Moderate; Do not describe how missing data were addressed. No evidence of selective reporting. | High
Cameron 2021 | Moderate; Inpatients enrolled in a larger study. Required diagnosis of active substance use and suicidal ideation at time of admission. Do not report whether consecutive patients were approached for participation. | Low; Cross-sectional study. No attrition reported. | Moderate; MIES was used to assess MI for all participants. No information on missing data. | Low; Mental health correlates assessed with validated measures in the same manner for all participants. | Moderate; Controlled only for depression symptoms. | Moderate; Do not describe how missing data were addressed. No evidence of selective reporting. | Moderate
Currier 2015; Currier 2015 | Moderate; Participants were recruited over a 2-year period at a community college. Do not report how many potential participants declined participation. | Low; Cross-sectional study. No attrition reported. | Low; MIQ-M was used to assess PMIE exposure for all participants. Amount of missing data not reported, but missing data were handled using multiple imputation. | Low; Mental health correlates assessed with validated measures in the same manner for all participants. | Moderate; Controlled for age, ethnicity, gender, branch of service, number of deployments, months since most recent deployment, and exposure to traditional combat stressors. Other potential confounders not considered. | Low; Analyses were appropriate and no evidence of selective reporting. | Moderate
Currier 2018 Study 1; Currier 2019 | Moderate; Invitations were mailed to all students from 2 universities utilizing GI Bill funding. 26.4% responded to the invitation. Included individuals with a deployment who endorsed MI. | High; For Currier 2019, 65% of participants completed the follow-up assessment. Participants who did not complete the follow-up were not included in analyses. Completers and non-completers did not differ in their levels of MI-related outcomes or mental health symptoms at T1. | Low; EMIS-M was used to assess MI for all participants in the same manner. Only included participants who completed measure and endorsed MI. | Low; Mental health correlates assessed with validated measures in the same manner for all participants. | High; Baseline depression symptoms were included in the model as a covariate. Other potential confounders not considered. | Low; Analyses were appropriate and no evidence of selective reporting. | Moderate
Currier 2018 Study 2 | Moderate; Anonymous online survey was distributed by Qualtrics to 8,800 individuals with an indication of military experience in their profiles. 3,200 individuals responded affirming military service. Of these, 19.5% were included in the study. | Low; Cross-sectional study. No attrition reported. | Low; EMIS-M was used to assess MI in the same manner for all participants. No missing data on this measure due to forced responses in online survey. | Low; Mental health correlates assessed with validated measures in the same manner for all participants. | High; Analyses did not account for potential confounders. | Low; Analyses were appropriate and no evidence of selective reporting. | Moderate
Currier 2020 Study 2 | Moderate; Online survey distributed via Qualtrics. Limited to post-9/11 Veterans due to over-representation of older Veterans in initial sample. Included Veterans who served in a combat operational role during deployment. | Low; Cross-sectional study. No attrition reported. | Low; EMIS-M and EMIS-M-SF were used to assess MI in the same manner for all participants. No missing data on this measure due to forced responses in online survey. | Low; Mental health correlates assessed with validated measures in the same manner for all participants. | High; Analyses did not account for potential confounders. | Low; Analyses were appropriate and no evidence of selective reporting. | Moderate
Evans 2018 | Moderate; Participants were from a larger study that recruited Veterans with religious/spiritual struggles from a VAMC. Participants were self-referred from advertisements. 23 participants without responses on the MIES were omitted from the study. | Low; 2 participants were lost to follow-up. | Low; MIES was used to assess PMIE exposure in the same manner for all participants. Participants included in the study had no missing data on scale or item levels. | Low; Mental health correlates assessed with validated measures in the same manner for all participants. | High; Analyses do not account for potential confounders. | Low; Analyses were appropriate and no evidence of selective reporting. | Moderate
Fernandez 2023 | High; Data from a baseline survey of Veterans prior to participation in a nonprofit-run retreat to Israel. Authors note that most participating Veterans have higher levels of distress than community samples. This study only included retreat participants who were married or in a domestic partnership (64%). | Low; Cross-sectional study. No attrition reported. | Moderate; EMIS-M was used to assess MI-related outcomes for all participants. No information on missing data provided. | Low; Mental health correlates assessed with validated measures in the same manner for all participants. | High; Analyses do not account for potential confounders. | Moderate; Do not describe how missing data were addressed. No evidence of selective reporting. | High
Forkus 2019 | Moderate; Online survey advertised via MTurk and conducted via Qualtrics. 29% of individuals who accessed the survey were ultimately included. Included Veterans who deployed to Iraq or Afghanistan. | Low; Cross-sectional study. No attrition reported. | Moderate; MIES was used to assess PMIE exposure in the same manner for all participants. No information on missing data. | Low; Mental health correlates assessed with validated measures in the same manner for all participants. | High; Analyses do not account for potential confounders. | Moderate; Do not describe how missing data were addressed. No evidence of selective reporting. | Moderate
Frankfurt 2017 | Moderate; Secondary analysis of data from a study that recruited Veterans at a VA hospital. From the parent study, selected only those who were male, had combat exposure, and had PTSD data. There were some differences between the sample for this study and the larger sample (race and war era). | Low; Cross-sectional study. No attrition reported. | High; A validated MI measure was not used. Instead, trauma narratives were coded for 8 transgressive acts. All included participants had trauma narratives. | Moderate; PTSD symptoms were assessed with a validated measure in the same manner for all participants. Suicidality was assessed with a single item from a PTSD measure. | High; Analyses do not account for potential confounders. | Low; Analyses were appropriate and no evidence of selective reporting. | High
Frankfurt 2018 | Moderate; Secondary analysis of data from a study that recruited Veterans at a VA hospital via posted advertisements, mailed letters, and referrals. Women and Veterans with PTSD or depression were oversampled with targeted mailings. If Veterans were in treatment, they were required to have stable regimens. Only included participants with data for DRRI and MIES. | Low; Retention between 2 assessment time points was 87%. | Low; MIES was used to assess betrayal and perpetration at time 2 only. Only participants with MIES data were included in the study. | Low; Mental health correlates assessed with validated measures in the same manner for all participants. | High; Analyses do not account for potential confounders. | Low; Analyses were appropriate and no evidence of selective reporting. | Moderate
Hamrick 2022 | Moderate; Women ADSMs and Veterans were recruited via online advertisements, word of mouth, flyers, and a university research pool. Data were collected over a 3-month period. | Low; Cross-sectional study. No attrition reported. | Moderate; EMIS-M was used to assess MI for all participants. Only the ‘other-directed’ subscale was used. 15% of data were missing. Missing data were handled with MLE. | Low; Mental health correlates assessed with validated measures in the same manner for all participants. | Moderate; Age, marital status, education, military status, military branch, and recruitment method were examined as possible covariates, but were not significant and thus not included in the model. Other potential confounders were not accounted for. | Low; Analyses were appropriate and no evidence of selective reporting. | Moderate
Held 2017 | High; Data were collected as part of standard intake evaluation for Veterans seeking mental health treatment. Veterans were enrolled in an IOP and had a primary diagnosis of PTSD. Excluded 17 Veterans without CAPS data. | Low; Cross-sectional study. No attrition reported. | Low; MIES was used to assess PMIE exposure in the same manner for all participants. No missing data. | Low; Mental health correlates assessed with validated measures in the same manner for all participants. | Moderate; Age and gender were examined as possible covariates but were nonsignificant and not included in final model. Other potential confounders were not accounted for. | Low; Analyses were appropriate and no evidence of selective reporting. | Moderate
Held 2021 | High; Participants were from the combat trauma track of an intensive PTSD treatment program. Data for the study were from assessments that occurred during routine clinical care. | Moderate; Program completion rates not reported. | Moderate; MIES was used to assess PMIE exposure and psychological response in the same manner for all participants. Degree and handling of missing data not reported. | Low; Mental health correlates assessed with validated measures in the same manner for all participants. | Moderate; Models adjusted for age and sex. Other potential confounders not accounted for. | Low; Analyses were appropriate and no evidence of selective reporting. | Moderate
Jinkerson 2019 | Moderate; Recruited from Veterans Service Organizations. 76% of eligible combat Veterans invited to participate agreed to participate. | Low; Cross-sectional study. No attrition reported. | Moderate; MIQ-M was used to assess PMIE exposure in the same manner for all participants. No information on degree or handling of missing data. | Low; Mental health correlates assessed with validated measures in the same manner for all participants. | High; Analyses do not account for potential confounders. | Moderate; Do not describe how missing data were addressed. No evidence of selective reporting. | Moderate
Jordan 2017; Nash 2013 | Moderate; Sample drawn from a prospective study of active-duty Marines deploying to Iraq or Afghanistan. Current study used the final cohort which had the highest combat exposure and unit losses during deployment. | Moderate; PTSD assessed at 8-month follow-up. Attrition not reported. | Moderate; MIES was used to assess PMIE exposure in the same manner for all participants. Not all MIES items were used for Jordan 2017. Extent of missing data not reported, but MLE was used. | Low; Mental health correlates assessed with validated measures in the same manner for all participants. | High; Analyses do not account for potential confounders. | Low; Analyses were appropriate and no evidence of selective reporting. | Moderate
Keenan 2023 | Low; Participants were justice-involved Veterans in Veterans Treatment Court. Appears that most VTC participants during the study period participated in the surveys. | Moderate; 66% of participants who completed the MIS at baseline completed it at follow-up. | Moderate; Validation study for the measure used to assess MI (MIS). MIS was used to assess MI for all participants either online or via a paper version. 3% of participants did not complete the MIS at baseline, but it’s unclear whether data was missing for those who did complete the measure. | Low; PTSD assessed with a validated measure in the same manner for all participants. | High; Analyses do not account for potential confounders. | Low; Analyses were appropriate and no evidence of selective reporting. | Moderate
Kelley 2019 | Moderate; Participants were recruited from multiple sources among the community. No further details on recruitment provided. Sample was slightly younger, more likely to be female, married, and have attended college than the larger post-9/11 Veteran population. | Low; Cross-sectional study. No attrition reported. | Moderate; MIQ-M was used to assess PMIE exposure and was modified to also include items assessing MI symptoms. Assessment was conducted in the same manner for all participants. No information on degree or handling of missing data. | Low; Mental health correlates assessed with validated measures in the same manner for all participants. | High; Analyses do not account for potential confounders. | Moderate; Do not describe how missing data were addressed. No evidence of selective reporting. | Moderate
Kelley 2021a | High; Participants were US Air Force ISR personnel. Secondary analysis of a larger study limited to individuals who endorsed graphic media exposure and had data on gender, months working in ISR, combat exposure, MIEs, and PTSD symptoms. | Low; Cross-sectional study. No attrition reported. | Low; MIES was used to assess PMIE exposure in the same manner for all participants. Small changes were made to the measure for applicability to ISR personnel. Appears that only individuals with complete data were included. | Low; PTSD assessed with a validated measure in the same manner for all participants. | Moderate; Models included gender and months working in ISR as covariates. Other potential confounders not accounted for. | Low; Analyses were appropriate and no evidence of selective reporting. | Moderate
Kelley 2021b | Moderate; Veterans recruited via online advertising. No further information on recruitment reported. | Low; Cross-sectional study. No attrition reported. | Low; EMIS-M was used to assess MI in the same manner for all participants. No information on degree of missing data, but missing data were handled using full information maximum likelihood. | Low; Suicide ideation assessed with a single item from a validated measure in the same manner for all participants. | Moderate; Models included Veteran status, age, and PTSD disability status as covariates. Other potential confounders not accounted for. | Low; Analyses were appropriate and no evidence of selective reporting. | Moderate
Kinney 2023 | Moderate; Veterans eligible for VA care recruited via flyers, referrals, and intake clinics. Required history of mTBI. | Low; 98% of participants meeting inclusion criteria completed the study. | Low; MIES was used to assess PMIE exposure in the same manner for all participants. Only included individuals who completed the study measures (145/147). | Low; PTSD assessed with a validated measure in the same manner for all participants. | Moderate; Models adjusted for age and gender. Other potential confounders not accounted for. | Low; Analyses were appropriate and no evidence of selective reporting. | Moderate
Koenig 2020; Koenig 2018a; Koenig 2018b; Koenig 2018c; Ames 2018; Volk 2019 | Moderate; Majority of participants were Veterans recruited from outpatient clinics. Other participants recruited from a university or an online data collection platform. No further detail on sampling provided. | Low; A sub-sample (15%) completed the questionnaire a second time at 1–2-week follow-up for test-retest reliability but data of interest was cross-sectional. | Moderate; MISS-M was used to assess MI symptoms. Participants completed self-report measure either in person or online. Excluded data from participants missing > 50% of data for the subscales. For those whose data was included, missing data was handled with imputed means (1–7% for subscale items; 4% for missing subscales). | Low; Mental health correlates assessed with validated measures in the same manner for all participants. | Moderate; Models controlled for demographic, military, and social characteristics. Other potential confounders not accounted for. | Moderate; Missing data was addressed via imputed mean values for some analyses. No evidence of selective reporting. | Moderate
LaFrance 2019 | Moderate; Included consecutive patients seen by a single provider at a VAMC between 2012 and 2019. Participants had to be diagnosed with psychogenic nonepileptic seizures. Excluded 10 patients without MI information. | Low; Cross-sectional study. No attrition reported. | High; Did not use a validated measure of MI. Patient files were retrospectively reviewed for evidence of MI by a trained independent reviewer based on MI categories. | Low; Mental health correlates assessed with validated measures in the same manner for all participants. | High; Analyses do not account for potential confounders. | Moderate; Do not describe how missing data were addressed. No evidence of selective reporting. | High
Lancaster 2018a | Moderate; Online survey administered via Qualtrics software and posted on MTurk (paid for completing surveys). 32% of individuals who accessed the survey completed it. | Low; Cross-sectional study. No attrition reported. | Moderate; MIES and MIQ-M were used to assess PMIE exposure in the same manner for all participants. No information on degree or handling of missing data. | Low; Mental health correlates assessed with validated measures in the same manner for all participants. | High; Analyses do not account for potential confounders. | Moderate; Do not describe how missing data were addressed. No evidence of selective reporting. | Moderate
Lancaster 2018b | Moderate; Online survey administered via Qualtrics software and posted on MTurk (paid for completing surveys). 33% of individuals with military service who accessed the survey completed it. | Low; Cross-sectional study. No attrition reported. | Moderate; MIES was used to assess PMIE exposure in the same manner for all participants. Only self-transgressions and betrayals items were used. No information on degree or handling of missing data. | Low; Mental health correlates assessed with validated measures in the same manner for all participants. | High; Analyses do not account for potential confounders. | Moderate; Do not describe how missing data were addressed. No evidence of selective reporting. | Moderate
Litz 2018 | Moderate; Included baseline data from 3 trials of ADSMs deployed to Iraq/Afghanistan. No other information on recruitment or selection reported. Required to describe an event that met DSM-IV Criterion A1 and A2 for inclusion. | Low; Baseline data only. | High; Did not use a validated PMIE/MI measure. Categorized Criterion A event types (inlcuding MI-self and MI-others). No missing data; only individuals reporting an event were included. | Low; PTSD assessed with a validated measure in the same manner for all participants. | High; Analyses do not account for potential confounders. | Low; Missing data were minimal and handled via listwise deletion. Analyses were appropriate and no evidence of selective reporting. | High
Maguen 2020; Maguen 2022; Chesnut 2020; Nillni 2020 | Low; Potential participants were drawn from a roster of all service members separating in fall of 2016. Multiple contacts were made by mail with a link to the online survey, with a 23% response rate (completion of the baseline survey). The sample was demographically like the sampling frame, and weighting was used to adjust for observed nonresponse bias. | Low; Only participants who had wave 2 data (79%) were included in analyses for this study (MI was not assessed at baseline). | Low; MIES was used to assess PMIE exposure and subjective distress in the same manner for all participants. Missing data were handled using the Full Information Maximum Likelihood technique. | Low; Mental health correlates assessed with validated measures in the same manner for all participants. | Low; Adjusted ORs accounted for demographic and military characteristics including age, minority racial status, marital status, educational status, service branch, rank, military occupational specialty, number of deployments, combat exposure, military sexual trauma exposure, and premilitary trauma exposure. | Low; Analyses were appropriate and no evidence of selective reporting. | Low
Maguen 2023 | Low; Nationally representative sample of Veterans selected using a stratified, probability-based sampling frame from a dataset containing information on all separated Veterans between 2001 and 2015. Response rate to mailed invitations was 40%. | Low; Cross-sectional study. No attrition reported. | Low; MIES was used to assess PMIE exposure and subjective distress for all participants. Participants could complete the self-report measure online or by phone. Minimal missing data which were handled via multiple imputation. | Low; Mental health correlates assessed with validated measures in the same manner (online or by phone) for all participants. | Low; Adjusted models included age, race and ethnicity, sexual orientation, marital status, parental status, branch of service, rank, highest level of education, history of warzone deployment, MST, adverse childhood events, current mental health status (ie, traumatic stress, depression, anxiety, hazardous alcohol use), and pre-military history of suicidal ideation and suicidal self-directed violence. | Low; All analyses were weighted to account for sampling methods used. Analyses were appropriate and no evidence of selective reporting. | Low
McDaniel 2023 | Low; Nationally representative sample of US Veterans (using Qualtrics to recruit and link participants to the study). Sampling was stratified to oversample women and African American Veterans. | Low; Cross-sectional study. No attrition reported. | Moderate; The MISS-M-SF was used to assess MI in the same manner for all participants. No information on degree or handling of missing data. | Low; Mental health correlates assessed with validated measures in the same manner for all participants. | Moderate; Models controlled for gender, race, age, region of the United States, branch of military service, marital status, length of military service, annual income, military identity, daily stress, loneliness, and quality life. Other potential confounders not accounted for. | Moderate; Do not describe how missing data were addressed. No evidence of selective reporting. | Moderate
Nichter 2021; Norman 2022; Maguen 2023 | Low; Nationally representative sample of Veterans (sample drawn from a probability-based, online survey panel of US adults). Inclusion limited to Veterans with combat exposure. Post-stratification weights used 2019 US census data. | Low; Cross-sectional study. No attrition reported. | Low; MIES was used to assess PMIE exposure in the same manner for all participants. <4.5% missing data on MIES, which were imputed using chained equations. | Low; Mental health correlates assessed with validated measures in the same manner for all participants. | Low; Models adjusted for sociodemographic characteristics, combat exposure severity, lifetime trauma burden, and lifetime PTSD, MDD, AUD, and DUD. | Low; Analyses were appropriate and no evidence of selective reporting. | Low
Nieuwsma 2021; Nieuwsma 2022 | Moderate; Letters were mailed to Veterans identified from the VA Mid-Atlantic MIRECC’s Post-Deployment Mental Health Repository (3,000 recent-era Veterans). 33% of potential participants returned valid survey packets. | Low; Cross-sectional study (though some data were taken from original repository study). No attrition reported. | Moderate; MIES and MIQ-M were used to assess PMIE exposure in the same manner for all participants. BMIS was also used to assess MI sequela (not previously validated). Scale scores were calculated only for participants with 75% of responses for the measure. Means were imputed for missing values. For 2022 study, only 2 items from MIES were used. | Low; Mental health correlates assessed with validated measures in the same manner for all participants. | High; Analyses do not account for potential confounders in 2021 publication. In 2022 publication, model predictor variables included age, number of deployments, prior life stressors, combat experiences, post-battle experiences, gender, race, and highest rank. | Moderate; Analyses used available data. Do not report extent of missing data, but scale scores were not included for participants with < 75% of responses for a given measure. When < 25% of responses were missing, means were imputed for missing values. No evidence of selective reporting. | Moderate
Ogle 2018 | Moderate; Participants were US Air Force ISR personnel assigned to 3 units. Survey was offered anonymously by an embedded psychologist. Do not report how many potential participants declined participation. | Low; Cross-sectional study. No attrition reported. | Moderate; The MIES was used to assess MI in the same manner for all participants. The measure was adapted slightly to match up with the experiences of remote combat. No information on degree or handling of missing data. | Low; PTSD assessed with a validated measure in the same manner for all participants. | High; Analyses do not account for potential confounders. | Moderate; Do not describe how missing data were addressed. No evidence of selective reporting. | Moderate
Paige 2019; Bhalla 2018 | High; Participants drawn from the baseline sample of a longitudinal online study of Army couples after deployment. Recruitment materials directed potential participants to the website. Participants had to be in a heterosexual couple (male soldier and civilian female). Of the couples meeting criteria and invited to complete the survey, 81% participated. | High; For Bhalla publication, only soldiers with data at all 3 time points were included, and soldiers who were excluded for this reason had significantly more exposure to PMIEs (did not differ on other factors). Do not report how many were excluded. | High; Paige publication did not use a validated measure to assess PMIE/MI. Instead, assessed the frequency of 4 categories of trauma types, including MI by self and MI by others. No not report degree or handling of missing data. | Low; Mental health correlates assessed with validated measures in the same manner for all participants. | High; Analyses do not account for potential confounders except for combat exposure in Bhalla publication. | Moderate; Do not describe how missing data were addressed. No evidence of selective reporting. | High
Parry 2023 | Moderate; Data were derived from a database of Veterans who completed a routine PTSD intake assessment at a VA clinic. Appears that all first assessments were included within a given timeframe (Dec 2014 - Sep 2019). | Low; Retrospective review of health records. No attrition reported. | Low; The MIES was included on the PTSD intake form for all participants. Don’t report missing data for this measure, but overall data were missing for 3.8% of the cohort. | Low; Suicidality was examined for an 18-month follow-up period after the intake assessment using ICD codes from CDW data for all participants. | Low; Analyses adjusted for potential confounders identified through a literature review and consultation with experts: age, race, educational attainment, rurality, years of military service, depression diagnosis, TBI, tinnitus. | Low; Individuals with missing data were excluded during modeling, but missing data was minimal. No evidence of selective reporting. | Moderate
Presseau 2019 | Moderate; ADSMs were recruited Nov 2010 - June 2011 at an Army Medical Center during soldier readiness processing prior to deployment. Participants who returned for a follow-up assessment and provided sufficient information about their trauma to allow for categorization were included in this study. The final sample was older than those excluded from the initial sample. | Low; Cross-sectional study. Only participants who completed the follow-up were included in the study. | High; Did not use a validated measure to assess PMIE/MI. Instead, trauma type from Criterion A segment of SCID was coded using a coding scheme, including MI by self and MI by others. All participants were required to have enough information for coding trauma types for inclusion. | Low; Mental health correlates assessed with validated measures in the same manner for all participants. | High; Analyses do not account for potential confounders. | Moderate; Do not report extent of missing data but describe handling missing data using imputed means in models. When a measure for a given participant was missing more than 70% of the items, that score was treated as missing. No evidence of selective reporting. | High
Richardson 2022 | Moderate; Recruited using purposeful sampling via social media sites, military listservs, and flyers/newsletters. | Low; Cross-sectional study. No attrition reported. | Moderate; The MISS-M-SF and MIES were used to assess PMIEs/MI in the same manner for all participants. No information on degree or handling of missing data. | Low; Mental health correlates assessed with validated measures in the same manner for all participants, with the exception of self-harm/suicidal ideation, which were assessed with 2 ad hoc items. | High; Analyses do not account for potential confounders. | Moderate; Do not describe how missing data were addressed. Potential for selective reporting; only significant associations between variables that provided additional empirical support for the qualitative findings were discussed. | Moderate
Saba 2022 | Moderate; Veterans recruited via advertisements on social media and military listservs. 32% of potential participants (clicked on the ads) completed the survey. 34% of respondents were excluded for not passing validation checks. | Moderate; The present study included only participants who completed the 12-month follow-up (82%). | Low; The MIES was used to assess PMIE exposure at 12-month follow-up only in the same manner for all participants. 4 participants had missing data and were excluded from analysis. | Low; Mental health correlates assessed with validated measures in the same manner for all participants. | High; Analyses do not account for potential confounders. | Low; Excluded 4 participants (0.4%) with missing data from analyses. Analyses were appropriate and no evidence of selective reporting. | Moderate
Shapiro 2022 | Moderate; Data were collected from a subsample of female service members concurrently with a study of service members presenting for participation at a Joint Forces Training Center. Recruitment and sampling for that study are not described. | Low; Cross-sectional study. No attrition reported. | Moderate; The MIES was used to assess PMIE exposure in the same manner for all participants. Missing data not reported separately for this measure, but rates of missing data ranged from 8–39% across study variables. | Low; Suicide ideation assessed with a validated measure in the same manner for all participants. | High; Analyses do not account for potential confounders. | High; Listwise deletion was used to handle missing data and about half of participants were excluded from models. No evidence of selective reporting. | High
Stein 2012 | Moderate; Included ADSMs assessed as part of treatment for PTSD symptoms between August 2009 and December 2010. Participants were required to identify traumatic event currently causing the most distress and provide enough detail of the event for categorization. | Low; Cross-sectional study. No attrition reported. | High; Did not use a validated PMIE/MI measure. Categorized index event types (including MI-self and MI-others). No missing data - only participants with an index event were included. | Low; PTSD assessed with a validated measure in the same manner for all participants. | High; Analyses do not account for potential confounders. | Moderate; No information on extent or handling of missing data. Only report data for significant results. | High
Thomas 2022 | Moderate; Recruited Veterans MTurk. Authors note that this is a reliable method of obtaining samples representing the US population but do not report evidence of this. Of the 2,644 responses obtained, 19% met inclusion criteria and passed validation checks. | Low; Cross-sectional study. No attrition reported. | Low; The MIES was used to assess PMIE exposure in the same manner for all participants. Missing item-level data ranged from 15–24 participants missing 1–12 items. Missing data values were imputed using multiple imputation. | Low; Alcohol misuse was assessed with a validated measure in the same manner for all participants. | High; Analyses do not account for potential confounders. | Low; Analyses were appropriate and no evidence of selective reporting. | Moderate
Tripp 2016 | Moderate; Veterans were recruited from VAMC clinics for an alcohol intervention study. Inclusion criteria required prior deployment and hazardous alcohol use. | Low; Data from baseline assessment of an alcohol intervention study. | High; Did not use a validated measure to assess PMIE/MI. Instead, used the Combat Experiences scale of the DRRI and looked at killing in combat and firing a weapon. Any individual who did not answer the Killing item was excluded from analyses. Do not report degree of missing data. | Low; Mental health correlates assessed with validated measures in the same manner for all participants. | Low; Ethnicity/race, age, gender, alcohol use, and other types of combat were examined as potential covariates. | Moderate; Mean substitution was used to handle missing data for any measure that was 80% or more complete. Any dichotomous variables that were missing were excluded from analyses, except for the Firing/Killing variable. Do not report degree of missing data. No evidence of selective reporting. | Moderate
Usset 2019 | Moderate; Potential participants were identified from a database of a Midwest VA health care system. Letters were mailed to a random sample of Veterans with a PTSD diagnosis enrolled in care. Do not report how many eligible individuals did not participate. | Low; Cross-sectional study. No attrition reported. | Moderate; The MIES and MIQ were used to assess PMIE exposure in the same manner for all participants. Do not report degree of missing data for this measure or how missing data were handled. | Low; PTSD was assessed with a validated measure in the same manner for all participants. | High; Analyses do not account for potential confounders. | Moderate; Do not describe how missing data were addressed. No evidence of selective reporting. | Moderate
Williams 2019 | Moderate; Participants were recruited from VSOs and reported events that occurred during combat causing regret. | Low; Cross-sectional study. No attrition reported. | High; Two items modified from the MIES were used to assess acts of commission and omission in the same manner for all participants. No information on missing data. | Low; Mental health correlates assessed with validated measures in the same manner for all participants. | Moderate; Partial correlations done to remove shared variance with age, gender, and combat/postcombat experience. Other potential confounders not considered in analyses. | Moderate; Do not describe how missing data were addressed. No evidence of selective reporting. | Moderate
Wisco 2017; Corona 2019 | Low; Data from the second baseline cohort of a study that surveyed a nationally representative sample of US Veterans. A random sample of Veterans were sent a screening survey. 71% completed the screening survey; 93% of these individuals participated in the study. Post-stratification weights were applied based on demographic characteristics. The current study was limited to the 38% of participants with combat exposure. | Low; Cross-sectional study. No attrition reported. | Moderate; The MIES was used to assess PMIE exposure in the same manner for all participants. Do not report degree of missing data for this measure or how missing data were handled. | Low; Mental health correlates assessed with validated measures in the same manner for all participants. | Low; Included model that adjusted for demographics, combat severity, cumulative trauma burden, and lifetime mental disorders. | Moderate; Do not describe how missing data were addressed. No evidence of selective reporting. | Moderate
Youssef 2018 | Moderate; Veterans were recruited via advertisements and clinician referrals at a VAMC. Required that Veterans report prior deployment to a combat theater and presence of symptoms of PTSD and/or inner conflict for inclusion. No further detail on recruitment/sampling reported. | Low; Cross-sectional study. No attrition reported. | Moderate; The MISS-M was used to assess MI symptoms in the same manner for all participants. Entire subscales were missing in 7% of cases, in which case the average of completed subscale scores was imputed. Items were missing from subscales in 0–13% of cases, and the average of the answered subscale items was imputed in cases where <50% of items were missing. | Low; PTSD was assessed with a validated measure in the same manner for all participants. | Low; Models include demographic and military-related characteristics (including combat exposure and PTSD diagnosis), physical health/behaviors, and religious involvement as covariates. | Moderate; Data were excluded from analyses for a scale if >50% of items were missing; do not report how often this occurred. For scales/subscales where <50% of data was missing, means were imputed. No evidence of selective reporting. | Moderate

Abbreviations. ADSM=active-duty service member; AUD=alcohol use disorder; BMIS=Brief Moral Injury Scale; CAPS=Clinician-Administered PTSD Scale; DRRI=Deployment Risk and Resilience Inventory; DUD=drug use disorder; EMIS-M=Expressions of Moral Injury Scale – military version; EMIS-M-SF=Expressions of Moral Injury Scale – military version – short form; IOP=Intensive Outpatient Program; ISR=intelligence, surveillance, and reconnaissance; MDD=major depressive disorder; MI=moral injury; MIES=Moral Injury Events Scale; MIQ-M=Moral Injury Questionnaire – military version; MIRECC=Mental Illness Research, Education, and Clinical Center; MIS=Moral Injury Scale; MISS-M=Moral Injury Symptom Scale – military version; MLE-maximum likelihood estimation; mTBI=mild traumatic brain injury; MTurk=Amazon Mechanical Turk; PMIE=potentially morally injurious event; VAMC=VA Medical Center; VTC=Veterans Treatment Court.

## STRENGTH OF EVIDENCE ASSESSMENTS

Outcome | Exposure Type | Studies | Study Limitations | Directness | Consistency | Precision | Rating and Summary of Evidence
Suicidal thoughts and behaviors | PMIE | 15 | High to low | Direct | Inconsistent | Imprecise | Low; PMIE exposure may be positively correlated with increases in suicidal thoughts and behaviors based on 15 studies.
Suicidal thoughts and behaviors | MI | 9 | High to moderate | Direct | Inconsistent | Imprecise | Low; MI symptoms may be positively correlated with increases in suicidal thoughts and behaviors based on 9 studies.
PTSD | PMIE | 29 | High | Direct | Inconsistent | Imprecise | Low; PMIE exposure may be positively correlated with greater PTSD symptom severity based on 29 studies.
PTSD | MI | 12 | High to moderate | Direct | Consistent | Precise | Moderate; MI symptoms may be positively correlated with greater PTSD symptom severity based on 12 studies.
Depression | PMIE | 22 | High to low | Direct | Inconsistent | Imprecise | Low; PMIE exposure may be positively correlated with greater depression symptom severity based on 22 studies
Depression | MI | 8 | Moderate | Direct | Consistent | Precise | Moderate; MI symptoms are likely positively correlated with greater depression symptom severity based on 8 studies.
Anxiety | PMIE | 8 | High to low | Direct | Inconsistent | Imprecise | Low; PMIE exposure may be positively correlated with greater anxiety symptom severity based on 8 studies.
Anxiety | MI | 5 | Moderate | Direct | Consistent | Precise | Moderate; MI symptoms are likely positively correlated with greater anxiety symptom severity based on 5 studies.
Substance use | PMIE | 11 | High to low | Direct | Inconsistent | Imprecise | Low; PMIE exposure may be positively correlated with greater substance use based on 11 studies.
Substance use | MI | 7 | Moderate | Direct | Inconsistent | Imprecise | Low; MI symptoms may be positively correlated with greater substance use based on 7 studies.
Functioning | PMIE/MI | 3 | High to low | Direct | Consistent | Imprecise | Low; PMIE exposure/MI symptoms may be positively correlated with greater impairment of relationship functioning and social engagement based on 3 studies.

Abbreviations. MI=moral injury; PMIE=potentially morally injurious event.

## FOREST PLOTS FOR INCLUDED META-ANALYSES

Suicidality (PMIE Exposure)

Suicidality (MI Symptoms)

PTSD (PMIE Exposure)

PTSD (MI Symptoms)

Depression (PMIE Exposure)

Depression (MI Symptoms)

Anxiety (PMIE Exposure)

Anxiety (MI Symptoms)

Substance Use (PMIE Exposure)

Substance Use (MI Symptoms)

Relationship/Social (PMIE Exposure & MI Symptoms)

## PEER REVIEW COMMENTS AND RESPONSES

Comment # | Reviewer # | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | 1 | Yes | None
2 | 2 | Yes | None
3 | 3 | Yes | None
4 | 4 | Yes | None
5 | 6 | Yes | None
6 | 7 | No - Overall, this is an important review that provides important information about the distinction of MI from traditional mental health diagnoses or challenging symptoms while showing that there are important correlations. The individual methods to address KQ1 and separately KQ2 are strong. However, there is room to clarify the rational for and potential impact of the significantly different inclusion/exclusion criteria for articles used to address the two key questions. There is also an opportunity to clarify the definition of MI and PMIE used to specifically screen articles for inclusion in the two key questions for the present review. This clarification is especially important for users of the review who may not have an in-depth familiarity with MI and PMIEs or who are utilizing the executive summary of the review as opposed to the entire review detail. | Thank you for this comment. The differences in eligibility criteria for the 2 Key Questions of the review are due to the differences in aim and scope of the Key Questions. The report has 2 distinct aims: 1) characterizing the literature on moral injury over time, broadly across populations; and 2) examining the association between MI/PMIE and mental health outcomes specifically in US Veterans/military service members. An examination of this association in other populations was outside of the scope of this review, which was developed in response to the needs of the Operational Partners. We have added some text to clarify the scope of the report.; Because there is not wide consensus on the definitions of the concepts of PMIE/MI, we included any studies where PMIE/MI was the main focus of the study, as defined by the study authors. We did not include studies that solely used the term “moral distress,” or studies that included moral injury or PMIE exposure only as a secondary outcome. We have added some text to the methods section to further clarify our approach.
7 | 8 | Yes | None
Is there any indication of bias in our synthesis of the evidence?
8 | 1 | Yes - The reviewers failed to take into account internal validity issues within studies, most notably, measurement problems, and specifically psychometric development and content validity problems (and misuse of scales that assess reports of exposure to potentially morally injurious events as indicators of moral injury as an outcome). | In our synthesis of the association between PMIEs/MI symptoms and mental health outcomes, we closely examined the measures used by each study (and how they were used) and differentiated between reports of PMIE exposures and MI outcomes in our narrative synthesis and quantitative analysis. We have added a table to the methods section that more explicitly describes this process.; The aim of this report was to examine the relationship between PMIEs/MI and mental health symptoms; it was beyond the project’s scope to evaluate the theoretical soundness or validity of individual PMIE or MI measures. Nonetheless, we discuss the variation in how individual measures/studies have conceptualized and operationalized these constructs and highlight potential limitations this inconsistency may produce. In addition, we note that despite this variability, findings are mostly consistent across studies, suggesting that the evidence is fairly robust despite measurement issues that may be present in available studies.
9 | 2 | No | None
10 | 3 | Yes - Table 2 reports characteristics of moral injury interventions for veterans and military service members. It seemed unusual to me that the Building Spiritual Strength (BSS) intervention was omitted. In fact, I believe there are more published RCTs of BSS than any other intervention designed to address moral injury (citations included below). I report the omission as a potential indication of bias because BSS is co-facilitated by a mental health provider and chaplain. BSS is therefore an alternative to approaches developed by the Integrative Mental Health team who commissioned the review that also are co-facilitated by a mental health clinician and chaplain.; Harris, J. I., Usset, T., Voecks, C., Thuras, P., Currier, J., & Erbes, C. (2018). Spiritually integrated care for PTSD: A randomized controlled trial of “Building Spiritual Strength”. Psychiatry Research, 267, 420–428.29980120; Harris, J. I., Erbes, C. R., Engdahl, B. E., Thuras, P., Murray-Swank, N., Grace, D., ... & Le, T. (2011). The effectiveness of a trauma focused spiritually integrated intervention for veterans exposed to trauma. Journal of clinical psychology, 67(4), 425–438.21294116; There are numerous non-empirical papers that describe BSS as well.; Winkeljohn Black, S., & Klinger, K. (2022). Building Spiritual Strength: a Spiritually Integrated Approach to Treating Moral Injury. Current Treatment Options in Psychiatry, 9(4), 313–320.36466719 | We screened and excluded the 2 empirical studies on the Building Spiritual Strength intervention cited here because it is described as an intervention for spiritual distress in individuals with PTSD and does not explicitly mention moral injury or include moral injury measures as outcomes. However, given that it is considered to be an intervention for MI and was mentioned by multiple peer reviewers, we have now included a mention of these studies in the intervention section even though they were not formally included according to our study eligibility criteria.; We include other studies of interventions that were co-facilitated by a chaplain and mental health clinician that explicitly mention and assess moral injury.
11 | 4 | No | None
12 | 6 | No | None
13 | 7 | No | None
14 | 8 | No | None
Are there any published or unpublished studies that we may have overlooked?
15 | 1 | Yes - You mischaracterized Adaptive Disclosure and you are missing the latest RCT that compared AD-Enhanced with present centered therapy: Litz, B. T., Yeterian, J., Berke, D., Lang, A. J., Gray, M. J., Nienow, T., Frankfurt, S., Harris, J. I., Maguen, S., & Rusowicz-Orazem, L. (2024). A controlled trial of adaptive disclosure-enhanced to improve functioning and treat posttraumatic stress disorder. Journal of consulting and clinical psychology, 92(3), 150–164. 10.1037/ccp0000873 38358703; The following are instances of publications that used the MIOS or the MIDS:; Biscoe, N., Bonson, A., Nickerson, A., & Murphy, D. (2023). Factors associated with exposure to potentially morally injurious events (PMIEs) and moral injury in a clinical sample of veterans. European Journal of Trauma & Dissociation, 7(3). 10.1016/j.ejtd.2023.100343; Biscoe, N., & Murphy, D. (2024). Factors associated with well-being among treatment-seeking UK Veterans: A cross-sectional study. Journal of Military, Veteran and Family Health, advanced online publication. 10.3138/jmvfh-2023-0023; Espinola, C. W., Nguyen, B., Torres, A., Sim, W., Rueda, A., Beavers, L., Campbell, D. M., Jung, H., Lou, W., Kapralos, B., Peter, E., Dubrowski, A., Krishnan, S., & Bhat, V. (2024). Digital interventions for stress among frontline health care workers: Results from a pilot feasibility cohort trial. JMIR Serious Games, 12(1). 10.2196/42813; Nazarov, A., Forchuk, C. A., Houle, S. A., Hansen, K. T., Plouffe, R. A., Liu, J. J., Dempster, K. S., Le, T., Kocha, I., Hosseiny, F., Heesters, A., & Richardson, J. D. (2024). Exposure to moral stressors and associated outcomes in healthcare workers: Prevalence, correlates, and impact on job attrition. European Journal of Psychotraumatology, 15(1). 10.1080/20008066.2024.2306102; Nguyen, B., Torres, A., Espinola, C. W., Sim, W., Kenny, D., Campbell, D. M., Lou, W., Kapralos, B., Beavers, L., Peter, E., Dubrowski, A., Krishnan, S., & Bhat, V. (2023). Development of a data-driven digital phenotype profile of distress experience of healthcare workers during COVID-19 pandemic. Computer Methods and Programs in Biomedicine, 240. 10.1016/j.cmpb.2023.107645; Phelps, A. J., Madden, K., Carleton, R. N., Johnson, L., Carey, L. B., Mercier, J. M., Mellor, A., Baills, J., Forbes, D., Devenish-Meares, P., Hosseiny, F., & Dell, L. (2023). Towards a holistic model of care for moral injury: An Australian and New Zealand investigation into the role of police chaplains in supporting police members following exposure to moral transgression. Journal of Religion and Health, 62(6), 3995–4015. 10.1007/s10943-023-01908-2 37697218; Ritchie, K., D’Alessandro-Lowe, A. M., Brown, A., Millman, H., Pichtikova, M., Xue, Y., Altman, M., Beech, I., Karram, M., Hosseiny, F., Rodrigues, S., O’Connor, C., Schielke, H., Malain, A., McCabe, R. R., Heber, A., Lanius, R. A., & McKinnon, M. C. (2023). The hidden crisis: Understanding potentially morally injurious events experienced by healthcare providers during COVID-19 in Canada. International Journal of Environmental Research and Public Health, 20(6), 4813. 10.3390/ijerph20064813 36981725; Williamson, C., Baumann, J., & Murphy, D. (2022). Exploring the health and wellbeing of a national sample of UK treatment-seeking veterans. Psychological Trauma: Theory, Research, Practice, and Policy. 10.1037/tra0001356; Turgoose, D., & Murphy, D. (2024). Associations between adverse childhood experiences (ACEs) and complex-PTSD, moral injury, and perceived social support: A latent class analysis. European Journal of Trauma & Dissociation, 100463 . D’Alessandro-Lowe, A. M., Brown, A., Sullo, E., Pichtikova, M., Karram, M., Mirabelli, J., ... & Ritchie, K. (2024). Why are healthcare providers leaving their jobs? A convergent mixed-methods investigation of turnover intention among Canadian healthcare providers during the COVID-19 pandemic. Nursing Reports, 14(3), 2030–2060.39189282; D’Alessandro-Lowe, A. M., Karram, M., Ritchie, K., Brown, A., Millman, H., Sullo, E., Xue, Y., Pichtikova, M., Schielke, H., Malain, A., O’Connor, C., Lanius, R., McCabe, R. E., & McKinnon, M. C. (2023). Coping, supports, and moral injury: Spiritual well-being and organizational support are associated with reduced moral injury in Canadian healthcare providers during the COVID-19 pandemic. International Journal of Environmental Research and Public Health, 20(19), 6812. 10.3390/ijerph20196812 37835082; D’Alessandro-Lowe, A. M., Patel, H., Easterbrook, B., Ritchie, K., Brown, A., Xue, Y., ... & McKinnon, M. C. (2024). The independent and combined impact of moral injury and moral distress on post-traumatic stress disorder symptoms among healthcare workers during the COVID-19 pandemic. European Journal of Psychotraumatology, 15(1), 2299661.38334706; Hendrikx, L. J., & Murphy, D. (2024). Associations between International Trauma Questionnaire complex posttraumatic stress disorder symptom clusters and moral injury in a sample of UK treatment-seeking veterans: A network approach. Psychological Trauma: Theory, Research, Practice, and Policy, 16(3), 513.36701541; Tao, H., Nieuwsma, J. A., Meador, K. G., Harris, S. L., & Robinson, P. S. (2023). Validation of the Moral Injury Outcome Scale in acute care nurses. Frontiers in Psychiatry, 14, 1279255. 10.3389/fpsyt.2023.1279255 38094593; Griffin, B. J., Norman, S. B., Weber, M. C., Hinkson Jr, K. D., Jendro, A. M., Pyne, J. M., ... & Maguen, S. (2024). Properties of the modified self-forgiveness dual-process scale in populations at risk for moral injury. Stress and Health, e3413.38730552; Maguen, S., Griffin, B. J., Pietrzak, R. H., McLean, C. P., Hamblen, J. L., & Norman, S. B. (2024). Using the Moral Injury and Distress Scale to identify clinically meaningful moral injury. Journal of Traumatic Stress. | Thank you for this comment. The recent RCT on AD was not included in our report because it was published after the end date of our systematic literature search (February 2024). Because the moral injury evidence base is rapidly evolving, we would need to conduct an updated systematic search of the literature to identify recently published studies, rather than selectively include new publications (which could introduce bias). Unfortunately, conducting an updated systematic search of the literature and incorporating findings into the present review is not feasible. We have revised our description of Adaptive Disclosure to be consistent with the citation provided here.; Thank you for including citations on the MIOS and MIDS. We included several of these citations for KQ1 (Biscoe 2023; Espinola 2024; Nazarov 2024; Phelps 2023; D’Alessandro-Lowe 2023; D’Alessandro-Lowe 2024; Tao 2023). We also now include Nguyen 2023, Ritchie 2023, and Williamson 2022.; We excluded Biscoe 2023 for KQ2 because it was not conducted among US Veterans/military service members. Likewise, we excluded Espinola 2024, Nazarov 2024, Phelps 2023, D’Alessandro-Lowe 2023, D’Alessandro-Lowe 2024, and Tao 2023 for KQ2 because they were not conducted among Veteran/military samples.; Several studies were not included because they were published after the end date of our systematic literature search (Biscoe 2024; D’Alessandro-Lowe 2024; Hendrikx 2024; Griffin 2024; Maguen 2024; Turgoose 2024).
16 | 2 | Yes - https://pubmed.ncbi.nlm.nih.gov/38655683/ | This study was not included because it was published after the end date of our systematic literature search.
17 | 3 | Yes - See comment above about published studies on the Building Spiritual Strength intervention. Since Feb 2024, when the literature search was performed, several studies have been published that are likely to be influential and are more methodologically rigorous than most of the earlier studies included in the review (citations are below). With such a dynamic literature, I am sure that it is difficult to ensure that the review reflects the most up to date information.; The contribution of exposure to potentially morally injurious events to trajectories of posttraumatic stress symptoms among discharged veterans - a five-year study. Levinstein Y, Zerach G, Levi-Belz Y, Dekel R. Soc Psychiatry Psychiatr Epidemiol. 2024 Sep 20. doi: 10.1007/s00127-024-02766-3. Online ahead of print. PMID: 3930242639302426; Response styles to positive affect during a positive psychology intervention for veterans with PTSD and moral injury: Preliminary results from a moral elevation intervention pilot trial. McGuire AP, Rodenbaugh M, Howard BAN, Contractor AA. Psychol Trauma. 2024 Aug 29. doi: 10.1037/tra0001774. Online ahead of print. PMID: 3920743239207432; Using the Moral Injury and Distress Scale to identify clinically meaningful moral injury. Maguen S, Griffin BJ, Pietrzak RH, McLean CP, Hamblen JL, Norman SB. J Trauma Stress. 2024 Apr 24. doi: 10.1002/jts.23050. Online ahead of print. PMID: 3865568338655683; In addition, I am aware of a forthcoming systematic review of the psychometric properties of scales designed to assess morally injurious outcomes that provides more in depth critiques of the available measures (e.g., factor structures, response formats, scoring algorithms, etc.). I also am aware of a forthcoming manuscript that examines the prevalence of PMIE exposure and functionally impairing moral injury in nationally representative groups of three high-risk populations including veterans. If requested, I would be glad to share the measure review or general prevalence manuscript with the VA ESP authors to consider including in the current review, especially if the literature search will be updated prior to publication of the current review. | Because the moral injury evidence base is rapidly evolving, as noted in this comment, we would need to conduct an updated systematic search of the literature to identify recently published studies, rather than selectively include new publications (which could introduce bias). Unfortunately, conducting an updated systematic search of the literature and incorporating findings into the present review is not feasible.
18 | 4 | No | None
19 | 6 | Yes - This study may or may not meet the inclusion criteria for interventions: Harris, J. I., Usset, T., Voecks, C., Thuras, P., Currier, J., & Erbes, C. (2018). Spiritually integrated care for PTSD: A randomized controlled trial of “Building Spiritual Strength”. Psychiatry Research, 267, 420–428. 10.1016/j.psychres.2018.06.045 29980120 | See our response to comment #10 regarding the Building Spiritual Strength intervention.
20 | 7 | No | None
21 | 8 | Yes - Related to interventions, there is a newly published efficacy trial supporting AD for psychosocial functioning (Litz et al., 2024) and a newly published ACT-MI pilot trial (Walser et al., 2024), but these may not make sense to include based on the team’s search date. | These studies were not included because they were published after the end date of our systematic literature search. Please also see our response to comment #17.
Additional suggestions or comments can be provided below.
22 | 1 | You defined PMIEs too narrowly. You are missing personal acts of omission (failing to act) and being the direct victim of another’s transgressive behavior. | Thank you for your comment. We have edited our description of PMIEs in the background section to be more inclusive.
23 | 1 | Your language use is often too imprecise: (1) Regarding the use of the terms PMIEs and MI: It is critical that you refer to PMIEs as “reports of PMIEs” and ratings on scales of MI as an outcome as “reports of MI symptoms.” The only actual experience or behavior that is assessed with questionnaires is ticking off checklists or boxes on Likert-type scales. Anything assessed with questionnaires, including the PCL-5 and the PHQ-9, entail global retrospective best guesses about various experiences; | Thank you for your comment. Our choice of language to describe PMIEs and MI is consistent with language used to report other mental health outcomes that are not measured directly and are instead assessed via subjective self-report measures.
24 | 1 | (2) it is very difficult to discern which studies and which scales contributed to Table 3, which is the most important Table in the report, it seems. It appears that scales that should only be considered assessments of reports of PMIEs were used in the MI symptoms category. There may be instances when the authors treated these scales as outcomes, but you should not. This reveals a lack of attention to content validity of scales and a critical appraisal of the internal validity issues within studies. This is highly problematic; | Throughout our synthesis, we differentiated between measures primarily assessing PMIE exposure and measures primarily assessing MI outcomes. We have added a table to the methods section specifying which methods of PMIE/MI assessment were considered reports of PMIE exposure versus MI outcomes and added some text before that Table that reiterates which studies were included in each analysis.
25 | 1 | (3) under overview of included studies, you mention the term mental health diagnoses. How is this latter issue germane to your review? Did any study use a structured clinical interview to determine caseness for a mental health diagnosis? I don’t think this is the case. At best an investigator may have used a relatively arbitrary score threshold to determine caseness; | We have changed this text to state “mental health symptoms or diagnosis.”
26 | 1 | (4) you stated “Pooled correlations were generally larger and more consistent between MI symptoms and mental health outcomes compared to correlations between PMIE exposures and these outcomes. This trend suggests a closer relationship between experiencing MI and mental health symptoms compared to being exposed to PMIE and mental health symptoms.” Again, you are reifying symptoms and exposures. Experiencing of PMIEs and MI symptoms are not assessed with scales. | We have revised the wording of this sentence to improve clarity.
27 | 1 | Also, the findings of greater associations between reports of MI symptoms and PTSD and depression is not unexpected. First, in some scales there is item overlap (not the MIOS). Second, PTSD and depression overlap with any behavioral and mental health problems. Third, conceptually, because MI requires a life-stressor and is life-stressor-based (well, with the EMIS it is not and that is another problem), these life-stressors are behaviorally, biologically, and socially haunting and painful and thus avoided (like PTSD), and the social pain that is associated with MI causes anhedonia and dysphoria (problems that are also inherent in any behavioral health problem, clinically) | We concur, and we include a paragraph in the Discussion section highlighting many points about why these constructs are similar yet potentially distinct.
28 | 1 | (5) in the limitations section you mention the MIDS. This is unclear and inaccurate. PMIE exposure is a necessary element to the clinical problem of MI. Both are assessed at the same time. PMIE exposure on MI scales is not a predictor. It is a necessary for symptom endorsement. The MIDS assesses PMIEs and then indexes the MI items to that experience. I assume what you mean by “PMIE exposure outcomes rather than PMIE exposure” is a problem with the MIES and other questionnaires that assess reports of PMIEs. The MIES confounds reports of exposure and reports of being bothered by the experiences (the latter being completely inadequate as an index of MI symptoms). In any event, what you should say is that unlike prior scales, in the MIDS, MI symptoms are indexed to a specific PMIE. Also, they did this after the MIOS was published which also anchors MI symptoms to PMIEs, which you fail to mention. | We have revised the limitations section to more clearly describe limitations of existing measures and highlight that evidence using newer measures has been published since the end date of the systematic literature search that informed this review.
29 | 1 | The biggest problem that you fail to mention is that no scale other than the MIOS has sufficiently focused on content validity. Without sufficient content validity, the danger is that a scale like the MIDS does not fully capture the construct of MI (which it doesn’t). I think the following excerpt from Litz and Walker (in press). Moral Injury: An Overview of Conceptual, Definitional, Assessment, and Treatment Issues. Annual Review of Clinical Psychology might be useful to give you a sense of the content validity issues:; “The MIDS and the MIOS share several structural elements: (1) respondents are asked to endorse exposure to a PMIE. Both scales assess personal acts of commission or omission and witnessing transgressions; the MIOS also assesses being directly affected by the transgressive acts of others (including betrayal experiences); (2) the self-identified worst and most currently distressing experience is used to anchor reports of possible MI symptoms; (3) if no exposure is endorsed, the scale is not completed; and (4) respondents rate the impact of their worst event over the last month. Predictably, there is also content overlap between the two scales. The initial pool of MIDS items was generated by two authors, Shira Maguen and Sonya Norman, based on Litz et al. (2009) and their clinical experience as psychologists in the VA. They also received feedback from Veterans, and colleagues in healthcare and the first-responder community. Due to the shortcomings of Litz et al. (2009), whose theory nearly exclusively addressed the aftermath of personal transgressions, and the anecdotal and likely narrow understanding of MI among the stakeholders who judged item content (who may have construed MI as an outcome pertaining to personal transgressive acts of omission or commission), the authors’ item creation and selection process falls short with respect to content validity. The biggest concern in this regard is that the MIDS underrepresents the MI construct. It appears that the unique outcomes associated with bearing witness to grave inhumanity, observing others’ transgressions, or being the direct victim of others’ transgressive acts were not fully considered. The MIDS has one item that asks respondents the degree to which they “feel betrayed by leaders and institutions.” This single item may be problematic for several reasons: (1) it arguably is a rating of exposure to a betrayal experience, rather than reflecting content associated with betrayal experiences (i.e., externalizing outcomes); (2) it appears to rule out reports of (and potential feelings about) trust violations by peers, intimates, or stranger- and bystander-based experiences; and (3) it is unclear how ratings about how true the statement ‘I feel betrayed by leaders or institutions’ (the harm) would necessarily change in psychotherapy, versus the varied and lasting outcomes from a veridical harm. Perhaps the authors’ tacit theory is that judgments about the relative truth about being betrayed is the clinical problem, which may change if the treatment goal, for some reason, is to help someone change how true it is for them that they feel betrayed.; The strengths of the MIDS are that the scale: (1) was structured well (i.e., requiring exposure, constraining symptom reports to 1 month); (2) was validated on three occupational groups at risk for PMIE exposure; (3) has some very good psychometric characteristics; and (5) has a high degree of content validity with respect to the aftermath of personal transgressions. The trimmed 18-item scale was found to have excellent convergent validity with mental and behavioral health measures and there was a high degree of internal consistency, suggesting that the MIDS is unidimensional. Unfortunately, a simple bivariate correlation between two administrations completed 2-weeks apart suggested poor temporal stability (.68).; Litz et al. (2022) employed a bottom-up, grounded theory approach to develop operational definitions of the subconstructs of MI, which informed the item content for the MIOS. This approach was driven by a comprehensive, multicultural study aimed at discovering and validating the lasting mental and behavioral health impact of PMIEs. Hundreds of service members and Veterans in the US, Israel, England, Canada, and Australia were administered a semi-structured interview to assess participants’ reports of the lasting phenomenological impact of exposure to PMIEs. Psychotherapists with extensive experience helping Veterans with PTSD and other behavioral health problems in each country were also interviewed and asked to describe their observations of the impact of PMIEs among patients in their care. Litz et al. (2022) used qualitative data reduction and analysis techniques to extract invariant, content-valid, higher-order themes, appealing to theory, when necessary, which they operationalized as domains of impact (i.e., subconstructs) of PMIEs and specific components within those domains. Transcribed interview content that overlapped with PTSD and depression symptoms was excluded. els and operational definitions of the distinct domains of impact of MI were as follows: (1) alterations in self- and other-perception, defined as disruptions in how individuals define themselves or the world with respect to what they or others are capable of in terms transgression. This is similar to the construct of shattered assumptions about a just world and personal invulnerability (Janoff-Bulman 1992, Pearlman & McCann 1990); (2) alterations in moral thinking, which entails judging the self or others harshly, moralistically, and with condemnation (self-censure, grievance, embitterment), also posited by Herman (1992), Shay (1994), and Janoff-Bulman (1992); (3) social impacts, defined as alterations in degree of comfort with others, connectedness, social acceptance / belonging, and changes in the frequency and quality of engaging with others (see Bowlby 1988, Herman 1992, Litz et al. 2009); (4) moral emotions and moods, defined as predominant, pressing, and easily triggered moral emotions (see Herman 1992); (5) self-harming / sabotaging, defined as deliberate and non-deliberate behaviors that negatively impact functioning, impair health, personal safety, and quality of life / well-being (see Litz et al. 2009); and (6) changes in beliefs about life meaning and purpose, defined as alterations in individuals’ religious or spiritual beliefs and behaviors (e.g., Litz et al. 2009). The first part of the MIOS assesses PMIE exposure. The specific event-type options are “a stressful experience in which you”: (1) did something (or failed to do something) that went against your moral code or values; (2) saw someone (or people) do something or fail to do something that went against your moral code or values; and (3) were directly affected by someone doing something or failing to do something that went against your moral code or values. Individuals are asked whether any of these stressors occurred, and if yes, which type(s). The research version of the MIOS assesses whether a PMIE meets the Criterion-A definition of a traumatic event and uses a PTSD screener to assess the degree to which PTSD symptoms are currently present as well. In the research and brief versions of the MIOS, respondents are instructed to keep the worst event in mind and rate various outcomes experienced in the last month. Each version also entails a second part, which is an 8-item functioning scale based on the Brief Inventory of Psychosocial Functioning (BIPF; Kleiman et al. 2020) that asks respondents to rate the degree to which the MIOS symptoms endorsed made it hard for them to function across various domains. The authors posited that MI should only be considered a potential clinical problem if the symptoms significantly affect multiple domains of functioning.; The investigators generated a large pool of potential items for the MIOS from each domain of impact and components of the higher-order domains. The validated MIOS is a 14-item questionnaire that was found to be invariant and reliable across cultures and had two factors, which were 7-item subscales that the authors labeled as shame-related and trust-violation-related outcomes. The MIOS had strong structural and configural validity, internal consistency, and strong test-retest reliability. Total and subscale scores were also found to have strong convergent validity, and PMIE-endorsers had substantially higher MIOS scores compared to non-endorsers (Litz et al. 2022). Although the MIOS has been validated in a study group of acute care nurses (Tao et al. 2023), unlike the MIDS, it was initially validated solely on active-duty service members and Veterans (and clinicians). In addition, the incremental and discriminatory validity of the MIOS has yet to be examined.; The MIOS stands out because content validity is very strong, it has subscales that assess the unique internalizing outcomes that arise from personal transgressions and externalizing outcomes from being victimized by others’ transgressive acts, and the MIOS includes an index of the current functional impact of MI symptoms.” | We have revised the limitations section, which now mentions content validity as a limitation of the measures used by studies that we included for KQ2.
30 | 1 | You do a good job underscoring the internal validity issues that arise from cross-sectional studies. I would add: (1) the term risk should never be used (like PMIE exposure is a risk factor for PTSD). It is a correlate; and (2) directionality and mono-method problems cannot be ruled out; reports of symptoms may affect ratings of reports of exposure to PMIEs. Or there may be a general response bias in filling out surveys. And, of course, correlational findings may be affected by a host of third variables | Thank you for this comment. Correlations or any other effect measure may reflect causal (temporal) relationships, but these relationships cannot be confirmed with cross-sectional evidence. For this reason, we are careful to state that any risk or causal relationships discussed are potential in nature. We also highlight the possibility of confounding. We revised text in the background and discussion sections discussing studies reporting on the relationship between PMIE/MI and mental health to be more explicit regarding these limitations.
31 | 1 | You mention that no study has used the MIOS or the MIDS and this is not true. Some of these are obscure journals..; Biscoe, N., Bonson, A., Nickerson, A., & Murphy, D. (2023). Factors associated with exposure to potentially morally injurious events (PMIEs) and moral injury in a clinical sample of veterans. European Journal of Trauma & Dissociation, 7(3). 10.1016/j.ejtd.2023.100343; Biscoe, N., & Murphy, D. (2024). Factors associated with well-being among treatment-seeking UK Veterans: A cross-sectional study. Journal of Military, Veteran and Family Health, advanced online publication. 10.3138/jmvfh-2023-0023; Espinola, C. W., Nguyen, B., Torres, A., Sim, W., Rueda, A., Beavers, L., Campbell, D. M., Jung, H., Lou, W., Kapralos, B., Peter, E., Dubrowski, A., Krishnan, S., & Bhat, V. (2024). Digital interventions for stress among frontline health care workers: Results from a pilot feasibility cohort trial. JMIR Serious Games, 12(1). 10.2196/42813; Nazarov, A., Forchuk, C. A., Houle, S. A., Hansen, K. T., Plouffe, R. A., Liu, J. J., Dempster, K. S., Le, T., Kocha, I., Hosseiny, F., Heesters, A., & Richardson, J. D. (2024). Exposure to moral stressors and associated outcomes in healthcare workers: Prevalence, correlates, and impact on job attrition. European Journal of Psychotraumatology, 15(1). 10.1080/20008066.2024.2306102; Nguyen, B., Torres, A., Espinola, C. W., Sim, W., Kenny, D., Campbell, D. M., Lou, W., Kapralos, B., Beavers, L., Peter, E., Dubrowski, A., Krishnan, S., & Bhat, V. (2023). Development of a data-driven digital phenotype profile of distress experience of healthcare workers during COVID-19 pandemic. Computer Methods and Programs in Biomedicine, 240. 10.1016/j.cmpb.2023.107645; Phelps, A. J., Madden, K., Carleton, R. N., Johnson, L., Carey, L. B., Mercier, J. M., Mellor, A., Baills, J., Forbes, D., Devenish-Meares, P., Hosseiny, F., & Dell, L. (2023). Towards a holistic model of care for moral injury: An Australian and New Zealand investigation into the role of police chaplains in supporting police members following exposure to moral transgression. Journal of Religion and Health, 62(6), 3995–4015. 10.1007/s10943-023-01908-2 37697218; Ritchie, K., D’Alessandro-Lowe, A. M., Brown, A., Millman, H., Pichtikova, M., Xue, Y., Altman, M., Beech, I., Karram, M., Hosseiny, F., Rodrigues, S., O’Connor, C., Schielke, H., Malain, A., McCabe, R. R., Heber, A., Lanius, R. A., & McKinnon, M. C. (2023). The hidden crisis: Understanding potentially morally injurious events experienced by healthcare providers during COVID-19 in Canada. International Journal of Environmental Research and Public Health, 20(6), 4813. 10.3390/ijerph20064813 36981725; Williamson, C., Baumann, J., & Murphy, D. (2022). Exploring the health and wellbeing of a national sample of UK treatment-seeking veterans. Psychological Trauma: Theory, Research, Practice, and Policy. 10.1037/tra0001356; Turgoose, D., & Murphy, D. (2024). Associations between adverse childhood experiences (ACEs) and complex-PTSD, moral injury, and perceived social support: A latent class analysis. European Journal of Trauma & Dissociation, 100463.; D’Alessandro-Lowe, A. M., Brown, A., Sullo, E., Pichtikova, M., Karram, M., Mirabelli, J., ... & Ritchie, K. (2024). Why are healthcare providers leaving their jobs? A convergent mixed-methods investigation of turnover intention among Canadian healthcare providers during the COVID-19 pandemic. Nursing Reports, 14(3), 2030–2060.39189282; D’Alessandro-Lowe, A. M., Karram, M., Ritchie, K., Brown, A., Millman, H., Sullo, E., Xue, Y., Pichtikova, M., Schielke, H., Malain, A., O’Connor, C., Lanius, R., McCabe, R. E., & McKinnon, M. C. (2023). Coping, supports, and moral injury: Spiritual well-being and organizational support are associated with reduced moral injury in Canadian healthcare providers during the COVID-19 pandemic. International Journal of Environmental Research and Public Health, 20(19), 6812. 10.3390/ijerph20196812 37835082; D’Alessandro-Lowe, A. M., Patel, H., Easterbrook, B., Ritchie, K., Brown, A., Xue, Y., ... & McKinnon, M. C. (2024). The independent and combined impact of moral injury and moral distress on post-traumatic stress disorder symptoms among healthcare workers during the COVID-19 pandemic. European Journal of Psychotraumatology, 15(1), 2299661.38334706; Hendrikx, L. J., & Murphy, D. (2024). Associations between International Trauma Questionnaire complex posttraumatic stress disorder symptom clusters and moral injury in a sample of UK treatment-seeking veterans: A network approach. Psychological Trauma: Theory, Research, Practice, and Policy, 16(3), 513.36701541; Tao, H., Nieuwsma, J. A., Meador, K. G., Harris, S. L., & Robinson, P. S. (2023). Validation of the Moral Injury Outcome Scale in acute care nurses. Frontiers in Psychiatry, 14, 1279255. 10.3389/fpsyt.2023.1279255 38094593; Griffin, B. J., Norman, S. B., Weber, M. C., Hinkson Jr, K. D., Jendro, A. M., Pyne, J. M., ... & Maguen, S. (2024). Properties of the modified self-forgiveness dual-process scale in populations at risk for moral injury. Stress and Health, e3413.38730552; Maguen, S., Griffin, B. J., Pietrzak, R. H., McLean, C. P., Hamblen, J. L., & Norman, S. B. (2024). Using the Moral Injury and Distress Scale to identify clinically meaningful moral injury. Journal of Traumatic Stress. | Thank you for this comment We meant that no study meeting our eligibility criteria for KQ2 used the MIOS or MIDS. We have revised the text in the discussion section to be more specific.
32 | 1 | Your review of intervention studies is woefully uncritical, inaccurate, and not up to date: (1) The Elevation Online Intervention for Veterans Experiencing Distress Related to PTSD and Moral Injury study was a pilot feasibility project, not a confirmatory RCT. Only completers were analyzed and EMIS scores did not change. This is moot not only because nothing can be inferred from a null result but also because of Type-II error - the trial was underpowered and was not an actual trial; (2) your summary of Adaptive Disclosure is inaccurate. You are also missing the latest RCT that compared AD-Enhanced with present centered therapy: Litz, B. T., Yeterian, J., Berke, D., Lang, A. J., Gray, M. J., Nienow, T., Frankfurt, S., Harris, J. I., Maguen, S., & Rusowicz-Orazem, L. (2024). A controlled trial of adaptive disclosure-enhanced to improve functioning and treat posttraumatic stress disorder. Journal of consulting and clinical psychology, 92(3), 150–164. 10.1037/ccp0000873 38358703 : (3) I would not include case studies. They have no confirmatory scientific value; (4) Impact of killing was a pilot feasibility study, not a confirmatory superiority trial. The results cannot be used as confirmation of efficacy: (5) please review all interventions and do not include studies that are not actual RCTs or disaggregate the pilots and the studies with serious internal validity problems from the high quality RCTs. | The section of our report that reviews interventions is part of KQ1, with the aim of characterizing published interventions only. We do not discuss the results of the studies or make any statements about intervention effectiveness. We did not assess study quality and cannot report which studies were higher quality. We report smaller studies and case studies because our aim is to describe interventions that have been studied, regardless of what can be gleaned from the study results. That said, our language was imprecise and incorrect in some places (ie, we should not have stated that these studies ‘evaluated the efficacy of interventions’) and we have revised the text to make a clearer distinction between trials and smaller pilot studies.; See our response to comment #15 about Adaptive Disclosure. We did not include the last AD trial because it was published after the end date of our systematic literature search.
33 | 1 | The Table on page 5 is problematic. First, there is no concern about the psychometric development and content validity of the scales. This is a huge problem. It is critical not to reify the results of studies that use psychometrically invalid scales as suggesting something about the construct of MI. For example, items for the MIS were “...generated by three psychologists who had worked for over 12 years with veterans diagnosed with PTSD. The items reflected the statements made by veterans about their emotional suffering and distress. These psychologists observed that the veterans they were treating were describing deeper core issues that accompanied their PTSD symptoms. These issues were identified as unresolved loss, guilt, and shame, the same issues that now have been identified as MI...” This reflects zero attention to content validity. Also, the MISS was created by compiling items from existing outcome scales that the authors judged to be face valid. Additional items that putatively assessed domains not assessed in existing scales were derived by the authors or from other studies. In other words, the authors failed to follow state-of-the-art steps in test construction and validation and failed to establish content validity, to ensure the construct coverage and the meaningfulness of scale items. Prior to the MIOS and the MIDS, the only face valid measure of MI as an outcome was the EMIS. The problem with the EMIS is that content validity was not sufficiently ensured, the scale does not require exposure to at least one PMIE, and the there is no time period for the ratings (the ratings could be about experiences in the distant past or a cumulative trait judgement about lifespan experiences). Given that the MIOS and the MIDS have not been used in epi studies to date, the EMIS is a less than ideal but acceptable measure of MI as an outcome.; Second, it is critical for you to understand that the MIES is not a measure of MI as an outcome. It is at best a measure of reports of exposure to SOME military-related PMIEs. I can give you citations where we critically examined the MIES. The MIES has items that cover reports of personal acts of commission and omission, respectively, bearing witness to transgressive behavior, and three items pertaining to betrayal experiences (by leaders, peers, and others outside the military). All items except the betrayal items include yoked questions about whether the person is “troubled by” each experience. Because the MIES has these “troubled by” items, some researchers have used the MIES to index MI as an outcome. This is unacceptable because the term is vague and can only suggest some degree of unspecified distress. Consequently, the MIES is not a valid measure of MI as an outcome (it fails to assess diverse and specific outcomes specific to the aftermath of PMIEs). This means that you cannot draw any inferences about MI as an outcome from studies that used it to indicate associations between MIES scores and other outcomes. Yet, you did this.; In this Table and conceptually in your meta-analysis, the exposure scales and results from them need to be disaggregated from the scales that assessed the putative outcome of MI. (the SCID and the Differential Emotions Scale-IV and Deployment Risk and Resilience Inventory-2 should be taken off the list. In the study that used the SCID, we simply typed Criterion-A event descriptions from the PTSD module. The SCID was not used to formally assess reports of exposure to PMIEs rather we determined whether Criterion-A events were morally injurious in an epi study. A scale that assesses reports of emotions such as shame and anger is not a scale that measures the construct of MI, and the DRRI is not a measure of MI by any means. This underscores the lack of critical appraisal of the content and methodological validity of the studies you employed in your review. | A thorough examination of the psychometric development and validity of measures was outside the scope of this review. Our intent with the mentioned table was to report the measures that have been used in the literature and not to critically evaluate them. However, based on this feedback, we removed this table to avoid misleading readers. We instead included a table in the methods section specifying which measures were included for which analyses.; We did not consider the MIES to be a measure of MI symptoms. Studies using this measure were included only in the PMIE exposure category of our synthesis. We added some information about the MIES to the background section.; For KQ2, we included studies that reported quantitative data on the relationship between PMIE exposures and mental health outcomes, even when PMIE exposures were not assessed formally with a PMIE measure. Specifically, we included studies that retrospectively categorized traumatic events experienced by individuals as PMIEs. In the process of evaluating each study’s risk of bias using the QUIPS tool, we considered whether the study used a validated measure of PMIE exposures and when studies did not, we rated the risk of bias for the ‘prognostic factor measurement’ domain as ‘high.’; Similarly, 1 included study examined the association between specified ‘symptoms of moral injury’ (ie, sorrow, regret, shame, and alienation) using non-MI scales (Differential Emotions Scale-IV and Deployment Risk and Resilience Inventory-2). We also rated this study as high risk of bias for the ‘prognostic factor measurement’ domain of the QUIPS.
34 | 1 | Flow diagram doesn’t explain why so many studies were excluded so it is unclear why more couldn’t have been included. | Studies were excluded when they did not meet the eligibility criteria as described in our methods. KQ2 was limited to studies of US Veterans or military service members, and several studies conducted in other populations were therefore excluded. We also limited study inclusion for KQ2 to studies reporting a quantitative association between MI/PMIE and a specified mental health outcome.
35 | 1 | A good proportion of total published MI studies (80/279=28.6%) supposedly did not use a measure of PMIEs or MI, and it is unclear what those studies did and/or how they were published without using a measure (see table on pg. 12) - perhaps they just used single items to ask about PMIEs and then looked at other outcomes? This poses substantial internal validity problems, which means nothing substantive should be inferred about PMIE and MI as an outcome. | The first aim of this report was to describe and characterize the current state of the literature on moral injury. Many early studies do not use published measures, but instead ask participants in a survey about their experiences related to moral injury or PMIEs. We do not use these studies to reach any conclusions about moral injury – we are only describing the published literature. For KQ2, several studies did not use a measure to assess MI/PMIE exposure. These studies examine the association between reported exposure to PMIEs and mental health outcomes. This limitation was taken into account during during the process of evaluating study’s risk of bias (also see our response to comment #33).
36 | 1 | The way you coded studies was strength of evidence and your criteria for “imprecision” and “bias” were never defined clearly so hard to know what the criteria were for this or if it could be replicated. | We used the AHRQ methods guide (cited in our methods section) to make strength of evidence assessments and we follow AHRQ methods to evaluate the domains of imprecision and bias. The study limitations domain is based on our assessment of the risk of bias of each study and we used the QUIPS tool (also cited in our methods section) for this step. We evaluated imprecision based on the confidence intervals from the meta-analysis.
37 | 1 | You don’t have the search terms for the review so hard to know how to replicate the findings. | The search strategy for the review is provided in the beginning of the Appendix.
38 | 1 | Under future research, the language needs more precision. What does explore innovative treatments addressing PMIE exposure mean? Treatments that prevent exposure? And, what do you mean by MI symptom sequelae? PTSD and depression? I would state explicitly that clinical trials of putative MI treatments need to use a scale that measures MI symptoms and functional impact as the primary endpoint / outcome. None to date have. | We revised this section to improve clarity. We also now recommend that future intervention studies use MI-specific measures as primary outcomes.
39 | 2 | Page 4 line 18: “moral transgressions related to self-directed actions (commissions) and other-directed actions including failing to act (omissions).” Omission is correctly defined (failing to act) but should be conceptualized as a self-directed not other-directed action | Thank you for your comment. We have edited the text to correctly include omission as a self-directed action.
40 | 2 | Table 1 page 5: need to make it clear if scales are measuring PMIE indexed to morally injury symptoms (i.e., connecting the two) as this is not clear from table (only whether these are measured or not). Also please note that there is more than one Table 1 in the document so may need to renumber for clarity. | Reviewing the psychometric properties of measures was outside the scope this review. We removed the mentioned table to avoid misleading readers. Please also see our response to comment #33.
41 | 2 | Table 1 page 12: The MIDS is not included in this table nor in the subsequent figures despite having two published studies (and many more in process). It seems that other measures with two published studies are included in this table. | We only identified a single study using the MIDS that was published prior to the end of our systematic literature search (February 2024).
42 | 2 | I am not clear why intervention with ref #52 is included for moral injury-this seems much more like a PTSD related intervention for sexual assault survivors. | This intervention was developed for individuals with both PTSD and MI. We revised the description of this intervention to improve clarity.
43 | 2 | Table 2 p 14. Please add if these are individual or group interventions | We added this information to the Table.
44 | 2 | I am not clear about why the two population-based studies for suicide outcomes were not included in analysis? This could be a source of bias? | These studies were not included in quantitative analyses because of how their data was reported (odds ratios or risk ratios), but they still contribute to the strength of evidence assessments for that outcome.
45 | 3 | Table 1 reports characteristics of measures of moral injury. To increase the utility of the table for researchers and clinicians tasked with selecting a PMIE/moral injury measure for their specific purposes, I would expect to see additional information presented. For example, to my knowledge, the MISS and MIDS are the only two measures listed in the table that have published empirically supported scoring algorithms suggesting that responses on the scale can be aggregated into either (1) a continuous composite score where higher values representing increasing severity and (2) a discrete score representing the presence/absence of clinically significant and functionally impairing levels of moral injury. This can be an incredibly valuable tool to enhance efficient screening for individuals likely to benefit from treatment focused on moral injury. Related, the available scales differ in attributes other than unidimensional/multidimensional factor structure, such as some that use unipolar response formats (e.g., Not at all to Extremely) versus bipolar response formats (e.g., Strongly Disagree to Agree). Finally, some but not all of the listed measures index moral injury outcomes to specific potentially morally injurious event, which is a prerequisite for moral injury as suggested by the review authors. | It was not the aim of this review to evaluate the psychometric properties and limitations of scales that measure PMIE exposure or MI symptoms. We removed the mentioned table to avoid misleading readers. Please also see our response to comment #33.; We added text to the background section highlighting some issues with current measures, including the fact that some measures do not link outcomes to PMIEs.
46 | 3 | Table 2 reports characteristics of moral injury interventions for veterans and military service members. It seemed unusual to me that the Building Spiritual Strength (BSS) intervention was omitted. In fact, I believe there are more published RCTs of BSS than any other intervention designed to address moral injury (citations included below). These studies certainly fall within the time period for literature selection, and it is not clear to me why they would have been excluded based on the stated inclusion/exclusion criteria.; Harris, J. I., Usset, T., Voecks, C., Thuras, P., Currier, J., & Erbes, C. (2018). Spiritually integrated care for PTSD: A randomized controlled trial of “Building Spiritual Strength”. Psychiatry Research, 267, 420–428.29980120; Harris, J. I., Erbes, C. R., Engdahl, B. E., Thuras, P., Murray-Swank, N., Grace, D., ... & Le, T. (2011). The effectiveness of a trauma focused spiritually integrated intervention for veterans exposed to trauma. Journal of clinical psychology, 67(4), 425–438.21294116 | Please see our response to comment #10 regarding the Building Spiritual Strength intervention.
47 | 3 | The limitations section mentions that recently developed scales including the MIDS and MIOS measure moral injury outcomes rather than PMIE exposure. A more correct statement is that each of these measures assess morally injurious exposures and outcomes, linking the hallmark indications of moral injury endorsed by a respondent to a specific event or series of related potentially morally injurious events. | We removed this statement regarding MIDS and MIOS, and now only state that newer measures have been developed in recent years to overcome some of the limitations of prior measures.
48 | 3 | Given the focus in the results on the strength of evidence supporting each of the intervention approaches (e.g., pre-post open trial, RCT, etc.), I expected more specific future directions for clinical research in the discussion. For example, trials often did not include a control condition, and when they did it was not an active control (e.g., emerging evidence-based moral injury interventions were compared to wait-list rather than alternative treatment like evidence-based treatment for PTSD, other supportive therapy, or treatment as usual). Additionally, the authors point out in the review that trials often evaluated the effectiveness of moral injury interventions using a proxy measure for moral injury, such as the widely used PTSD Symptom Checklist. This is because until recently only measures of PMIE exposure were available, and PMIE exposure is assumed to be constant once it occurs (thus not amenable to change over the course of treatment). Given the conceptual arguments differentiating PTSD and moral injury in the review, I anticipated the authors would encourage future trials to use the newly developed measures of moral injury outcomes (e.g., MIDS, MIOS) that likely are more sensitive to change than the previously developed measures of PMIE exposure. | To clarify, we did not synthesize evidence on intervention effectiveness in this review. Rather, our aim was to characterize/describe moral injury interventions that we identified in the published literature. However, based on this feedback, we added a sentence to the future research section stating that MI intervention studies should use MI-specific outcome measures.
49 | 3 | The authors write “increasing” when I think they mean “increasingly” on page v line 14 and page vi line 36. | Thank you. We corrected these errors.
50 | 3 | On page 17 line 45, the authors state that five studies comprised primarily Black participants but give 8 citations. I did not follow the logic, given that when they described the number of studies for other groups the number of citations matched the number of studies described in the narrative. | Thank you. We corrected this error.
51 | 3 | It did not appear that the CHAI or NHVRS Abbreviations were reported in the Abbreviations table. There may be other abbreviations not reported in the table; however, these were the only two that I noticed. A careful proofread is warranted. | Thank you. We added CHAI and NHVRS to the abbreviations table and reviewed the report for other missing abbreviations.
52 | 3 | On page 26 line 42, the authors wrote “week” when the word “weak” was intended. | Thank you. We corrected this error.
53 | 4 | Pg8, ln14: should be “increasingly” | Thank you. We corrected this error.
54 | 4 | Pg28, ln 8: “Of the studies discussed in the previous section” is ambiguous. The previous section was discussing intervention studies, but this section has a larger purview. | Thank you; we changed the text to read “of the studies included for Key Question 1” to improve clarity.
55 | 4 | Pg28, ln 54: “No studies used the more recently published MIDS, MIOS, and MIS measures.” What about those validation studies themselves? Data from those validation studies includes cross-sectional findings on correlations between measures of moral injury and the mental health outcomes of interest. | The validation study for the MIOS was included for KQ1, but not for KQ2, since the data is from participants from multiple countries and KQ2 was limited to US studies. Similarly, the validation study for the MIDS was included for kQ1, but not for KQ2, since it includes data from non-Veteran/military service member participants and does not report separately on this subgroup.; Omission of the validation study for the MIS from KQ2 was an oversight and we now include this study.
56 | 4 | Pg37, ln 16: Should this read “...were conducted exclusively among recent era...”? Because, in fact, even more of the studies included post-9/11 veterans, just not exclusively so? If I understand the findings on the top of page 22, roughly 99% of studies at least included post-9/11 veterans, and only 1% of studies were among Vietnam Veterans. Does this merit a recommendation that more research should be conducted among non-post-9/11 Veterans, particularly Vietnam Veterans? | Yes, we mean that these studies only included recent era Veterans/military service members and have added ‘exclusively’ to the text where this is mentioned. We revised the future research section to highlight the need for more research to understand how PMIE/MI may impact Veterans of different service eras.
57 | 4 | How are PMIE Exposures vs. MI Symptoms measures determined? The report routinely differentiates between PMIEs and MI. However, I am unclear on how the findings denoted in the report (e.g., Table 3 and elsewhere) precisely distinguished between PMIE and MI for purposes of the differentiated results that are presented. Table 1 lists different measures of PMIEs and MI, but it is unclear from the table if certain measures were considered measures of PMIE and others of MI or if some of the measures were parsed to reflect both PMIE and MI. Please provide clearer description of how this discernment was made. | Thank you for your comment. We added a table to the methods section and some text to the results section that more clearly defines how we differentiated between PMIE exposure and MI symptoms.
58 | 4 | Is it possible that the relatively small association between PMIE/MI and suicidality has to do with the frequences of STBs and how STBs were measured? Specifically, suicide and suicide attempts are relatively low base rate occurrences, which could make it difficult to detect statistically significant findings in modestly sized samples. The very large CHAI study found quite substantial effect sizes in key populations – it was helpful to see the details of that study. Why was that one not included in the meta-analysis? Further, in the discussion, how do you square the finding from the present review of there being a small association between PMIE/MI and STBs with the Jamieson et al (2023) finding that PMIE “substantially amplifies the risk of suicide...”? It seems that both the CHAI study and Jamieson (2023) review suggest a more substantial relationship between moral injury and suicidality than found in the present review, a discrepancy that merits further explanation. | It is accurate that STBs are low base rate events, but this should not influence the magnitude of the correlation. The magnitude does have a relationship with the likelihood of statistical significance (with larger effects being more likely to be significant). For these reasons we interpret both magnitude and significance of findings throughout the report. A possible explanation for the lower magnitude of the STB relationship is that STBs are more distal from the PMIE than depression, anxiety, and PTSD. As such, there may be more factors that contribute to the likelihood of STBs.; The CHAI study could not be included in quantitative analyses because of how their data is reported, but the results still contributed to the strength of evidence assessments for that outcome.; We revised the text regarding Jamieson 2023 to more accurately state that, like our review, Jamieson 2023 found that exposure to morally injurious events is associated with suicide risk. We removed the phrase “substantially amplifies” (language used in the Jamieson 2023 manuscript) to avoid implying that our findings were meaningfully different from those of Jamieson 2023.
59 | 4 | It seems out of place to specifically name the MIDS in the Limitations question. The limitation the MIDS is noted as overcoming (i.e., distinguishing between exposure and outcomes) was already overcome by previously published measures such as the EMIS and MIOS. The MIDS is a recent example of a moral injury scale that seeks to disentangle exposure and outcomes, but the sentence in the Limitations seems to imply that this disentanglement is a novel contribution from the MIDS, which it is not. Recommend not specifically naming just this one measure here. Also, in stating that “no completed studies” were found using the MIDS, MIOS, or MIS, is the review not including the validation studies for any of these measures? And what about the EMIS? Relatedly, it seems premature to specifically name the MIDS but not other measures in the Future Research section. If multiple measures are to be named in this section, at the least, the MIOS should also be named here, as it had a very robust psychometric validation and is presently being used in VA clinical settings across the country as part of moral injury care; and the MIOS is also at present the only moral injury measure in BHL. As the present review did not purport to conduct a comparative evaluation of moral injury measures, caution is warranted in highlighting a specific measure for future research. That said, the authors should consider whether they would recommend studies to comparatively evaluate different measures. | Please see our response to comment #28.; Regarding inclusion of studies using the MIDS, MIOS, or MIS, please see our response to comment #55.
60 | 4 | Finally, there were two elements in the tables/figures that were unclear to me. On pg10, in the ES Table, what is meant by the “Estimates” in italics. Is this number derived from sample size and number of studies somehow, then used in the meta-analyses? Then, on pg21, in the literature flow diagram, I am unclear on exactly why studies were excluded at each of the stages. For example were 357 excluded based on title/abstract review (leaving 871 remaining)? Why were the 503 studies then excluded? Also based on title/abstract? | Estimates refers to the number of associations reported that were included in the meta-analysis. We found that different studies sometimes used data from the same or similar groups of participants, so we are distinguishing between the number of distinct samples of individuals versus the number of associations included in the analysis, which often meant multiple estimates were reported for the same sample of participants.; The literature flow diagram for this report has the added complexity of different eligibility criteria for the 2 Key Questions. 357 records were excluded during initial title/abstract review. After that, 503 records were excluded during review of full-text of the records. We have added some detail to the figure to clarify.
61 | 6 | p. ii line 53 – change affiliation for Keith Meador to “VA Mid-Atlantic MIRECC” | The affiliation has been corrected.
62 | 6 | p. v line 35 – Suggest omitting the word “combat,” which limits the scope of situations that are potentially morally injurious in a manner that does not reflect the fullness of potentially relevant military experiences (e.g., drone operators, training-related incidents, military sexual trauma). | Thank you for this suggestion. We have removed the word ‘combat’ from this sentence in both the Executive Summary and Background sections.
63 | 6 | p. v lines 35–36 – The line “Moral injury (MI) describes the potential responses to such exposures” makes it sound to me like MI is an umbrella term for all possible responses (i.e., all responses along a continuum that includes less severe forms of moral distress), rather than a distinctive, defined response. Given that definitional clarity is one of the challenges identified in this report, a revision such as the following may provide helpful clarification: “Moral injury (MI) describes a uniquely intense and distressing response to such exposures...” | Thank you for this suggestion. We revised the text based on this feedback.
64 | 6 | p. vi line 35 – change to “increasingly” | Thank you. We corrected this error.
65 | 6 | p. 4 lines 6–9 – mirror the changes on page v regarding the use of “combat” and description of MI | Please see the response to comment #62.
66 | 6 | Is it possible to offer any summative and/or evaluative feedback on the measures described in Table 1 to assist readers in identifying strengths and weaknesses in terms of development/psychometrics? | Please see our response to comment #33.
67 | 6 | p. 14 paragraph 2 – I appreciate the nuanced acknowledgement that several interventions that are commonly referenced as being for moral injury were actually intended for individuals with PTSD and possible distress associated with PMIE exposure. This highlights the importance of focusing on moral injury sequelae/outcomes in intervention development as distinct from PTSD treatments. | Thank you for this comment.
68 | 6 | p. 14 paragraph 3 – This paragraph summarizes interventions that are specifically developed to target moral injury and as such distinguishes them from those in the prior paragraph. However, the first words of that paragraph (“Only 1 intervention developed specifically to target MI” sends the message that there is only one such intervention. I suggest moving the first sentence to the end of the paragraph to retain the emphasis on the RCT for the MOVED intervention while also avoiding potential misinterpretation at the start of the paragraph. | Thank you. We revised this section to improve clarity.
69 | 6 | p. 15 line 6 – Suggest starting the description of the therapy group on a new line for consistent formatting | Thank you; we corrected the spacing.
70 | 6 | p. 15 line 6 – per the cited paper, the group is composed of 10 weekly group sessions (not “8–10”) | In the ‘participants and procedures’ section of this paper (Pernicano 2022), the authors state that there were 3 8-week and 4 10-week groups for this study. However, since the intervention itself was developed with 10 sessions, we have updated the table as suggested.
71 | 6 | To aid readers in digesting the information in Table 2, would it be possible to enhance the organization of this table, perhaps by grouping the interventions into sections and/or adding columns with more detail (e.g., individual vs. group; professionally facilitated vs. peer or self-led; developed/used with US SMs/Veterans vs. international)? | We have edited the table so that the interventions are grouped by study design, and have added some information to the table, including sample sizes, comparators, and information on delivery/format of the intervention (ie, who delivered the intervention, whether it was an individual or group intervention, and whether it was delivered face-to-face or online).
72 | 6 | p. 16 lines 10–11 – the case study presented in the referenced article did conclude with a public ceremony, but that was a facility-specific adaptation and not a core component of REAL. For accuracy, suggest omitting that sentence from the description and replace with “The three phases of the group focus on: inventorying losses, telling stories, and reclaiming lives.” (Text drawn from page 545 of the published article) | Thank you. We have revised the table accordingly.
73 | 6 | p. 19 line 33 – why were the two large population-based studies excluded from the meta-analyses? | These studies could not be included in quantitative analyses because of how their data was reported (odds ratios or risk ratios), but they still contribute to the strength of evidence assessments for that outcome.
74 | 6 | p. 24 line 30 – unclear what “MIE dimensions” means in this sentence. Types/categories of MIE? | Correct; this study referred to the PMIE subtypes of atrocities of war, psychological consequences of war, and leadership failure/betrayal as ‘MIE dimensions. Since this terminology is not used elsewhere in the report, we changed the description to ‘types’ and listed the types.
75 | 6 | p. 26 line 42 – change to “weak” | Thank you. We corrected this error.
76 | 6 | p. 27 line 5 states that it is unclear whether MI symptoms precede, follow, or co-occur with PTSD symptoms. Is that finding unique to PTSD symptoms, or should the sentence instead refer to all related MH symptoms? | Thank you for the suggestion. We changed the text to state ‘mental health symptoms.’
77 | 6 | p. 27–28 Limitations/Future Research sections – what is the rationale for specifically highlighting the MIDS for differentiating PMIE exposure and outcomes when it is not the only measure reviewed to do so? And what is the rationale for specifically advocating its use relative to other measures that also differentiate? One strength of the MIDS is that it was developed using diverse samples (e.g., healthcare workers), but there is no empirical evidence to suggest it outperforms other moral injury measures among veterans/service members. Furthermore, the Moral Injury Outcome Scale (MIOS) is currently being used across VA via the BHL and MHA platforms, so it seems prudent to acknowledge the clinical quality improvement efforts and forthcoming studies using that measure. | Please see our response to comment #28.
78 | 6 | A distinction between “PMIEs” and “MI” is made throughout the report in both the findings and the tables. However, I am unable to find how that distinction was defined. Was it based on the measure used in the study? If so, how were the different measures classified? For example, p. 19 line 28: “We identified 15 studies examining associations between PMIE exposures and STBs” – what was the criterion for identifying those 15 studies as pertaining to PMIE exposures? | Please see our response to comment #57.
79 | 6 | It would be helpful to have a master reference list that incorporates the various lists that occur in the report and appendices. | We have added references for all studies included in the review to the Appendix.
80 | 7 | The first finding of the report indicates that half of studies that have been published about moral injury (MI) or potentially moral injurious events (PMIEs) have been conducted among Veterans and military service members. However, the background definition of MI/PMIEs focuses almost entirely on MI/PMIEs on Veterans and military service members. For example, the opening sentence of the background starts by focusing on the experience of military service members. If half of the studies included for KQ1 were conducted outside of the Veteran or military service member or Veteran context (first finding noted in the review), it would be helpful to have a description of MI and PMIEs outside of the military service and/or Veteran context. This will help the reader understand the rational for inclusion or exclusion of specific studies from the descripting review for KQ1. | Thank you for this suggestion. We expanded the first paragraph in the background section to mention that the concept of MI is increasing being applied to non-military populations including health care workers.
81 | 7 | As the review notes, there are a range of definitions and conceptualizations of MI and PMIEs in the literature. As a result, it may be helpful to provide a summary definition used when determining the appropriateness for including or excluding articles from the kQ1 review regardless of the setting for the MI or PMIE (could even be in a call-put box so it will be easy to identify). | Please see our response to comment #6.
82 | 7 | While I could imagine the operational reason for having a significantly different set of inclusion/exclusion criteria for KQ1 and KQ2, the scientific and programmatic rational does not appear to be fully described. It would be helpful to specifically explain the scientific and pragmatic rational for describing the full set of literature for MI and PMIE for the descriptive review and then only including information on US service member and Veteran w the MI or PMIEs for the systematic review (KQ2). If feels somewhat unusual that you would describe a body of literature in KQ1 and then not include three quarters of the literature in the review for KQ2. While this difference in included articles may be appropriate, It would be helpful to have a clearer rational for this in both the summary and body of the review. | Please see our response to comment #6.
83 | 7 | Because KQ1 and KQ2 include a significantly different set of articles, the question is raised about whether the coeducations in KQ2 would be different if the entire body of literature included in KQ1 was included in KQ2. The importance of this topic is highlighted by the KQ1 result that only 1 of 16 interventions that have been studies for MI/PMIEs was designed specifically for MI among Veterans/military service members. While there is a paragraph in the discussion that compares results for KQ2 to a previous systematic review that included studies among people who are not Veterans/service members from the United States, this may have included different literature. If the data exist to specifically compare the characteristics of studies from KQ1 that included the type of correlation information that would have otherwise made them eligible for KQ2 if the include population and settings were broader to those studies in KQ2, that would be helpful un understanding the potential for having different results for the correlation between MI/PMIEs and mental health systems as a whole as opposed for just the specific population included in KQ2. Even if only the number of otherwise eligible articles that would have been included is available, that may be helpful. | An examination of the association between PMIE exposure/MI symptoms in non-US-Veteran/military service member populations was outside the scope of this review. The literature base on this topic is large and we needed to narrow the scope for feasibility, which we did in consultation with the Operational Partners. Unfortunately, we are not able to provide additional information about studies we did not include for KQ2.
84 | 8 | One area where clarification would be useful is more explicit context about why HCW studies were included to characterize the scope of the research on moral injury in the beginning in detail and then not consistently referenced later. It feels a bit disjointed to include a paragraph reflecting a summary of interventions for HCWs and then a table for interventions in Veterans/Service members. Additionally, it feels disjointed to not include a section of the ESP reporting on moral injury and mental health and functioning outcomes for HCWs. More context about why some domains are not reported on and consistency in reporting methods could be useful...maybe more clarification in this section would be helpful in this section: “of the studies discussed in the previous section, 49 studies...” Can the authors clarify which studies are being referencing from the previous section and why HCW studies are not included in this section? | Please see our responses to comment #6 and comment #83.; We revised the text to clarify ‘of the studies included for KQ1, 50 studies met criteria for inclusion for KQ2.’ HCW studies were included only for KQ1; the eligibility criteria specifies that KQ2 is limited to studies conducted among US Veterans and military service members.
85 | 8 | Related to measures of moral injury section and table, consistency in reporting would be useful. This writer wouldn’t ever refer to the MIES as a measure of moral injury. Authors identify the construct being measured, but it is confusing to refer to the MIES as a measure of moral injury in some places and not others. This writer would recommend modifying Table 1’s title to indicate what it represents (e.g., measures of PMIE exposure, moral distress, and moral injury). This writer also thinks it would be helpful if across the report measures like the MIES are not referred to as “moral injury” measures in the same way that a screener for PTSD would not be referred to as a PTSD measure. This could be problematic for future research and interpretation of previous work (e.g., the MIOS requires a very different level of rigor where functional impairment tied to PMIEs exposure and moral distress is explicitly assessed than a measure like the MIES). | Please see our response to comment #33.
86 | 8 | It could also be helpful to more explicitly nod to the different conceptual interpretations of moral injury rather than limiting the discussion to moral injury as a dimensional syndrome. Some investigators do not believe a certain number of symptoms give rise to moral injury, but instead are explicitly focused on the functions of an individual’s behavior related to moral distress when their behavior results in impairment in psychosocial functioning following exposure to PMIEs. Others believe a certain level/amount of signs or symptoms of moral injury is indicative of a syndrome where treatment is necessary. It could be helpful to represent the differences in conceptual framework across a few groups here. For instance, the underpinnings of moral injury according to AD are very different from the framework used to conceptualize moral injury in ACT. | Thank you for this comment. We removed the sentence referring to MI as a dimensional syndrome.
87 | 8 | This reviewer has some concerns about how information is described in the interventions section. Efficacy trials have been conducted for AD and TrIGR. The statement “studies evaluated the efficacy of 16 interventions for moral injury...” could be misinterpreted as the majority of these interventions (including IOK) are not actually efficacy trials but pilot trials or case studies. This reviewer wonders if it would be useful to include more detail in Table 2 about the design of trials including sample size, stage of research for each intervention referenced, and detail about the kind of comparison condition included (e.g., waitlist vs. PCT vs. no comparison condition) so that results aren’t misinterpreted or equated. For instance, IOK has a very different level of support than AD, but in reviewing both records on the table, this wouldn’t be recognizable to someone without an understanding of moral injury interventional literature as RCTs were conducted for both interventions (just with very different targets [acceptability pilot vs. efficacy trial], sample sizes and comparison conditions).; This reviewer also wonders about including Building Spiritual Strength (BSS). Was BSS excluded due to a lack of standardized moral injury measure? As the authors discussed, there are several interventions that were developed to target moral injury in the context of PTSD of which BSS is one and a large RCT was conducted.; Harris JI, Usset T, Voecks C, Thuras P, Currier J, Erbes C. Spiritually integrated care for PTSD: A randomized controlled trial of “Building Spiritual Strength”. Psychiatry Res. 2018;267:420–428. doi:10.1016/j.psychres.2018.06.045 29980120; Additionally, this reviewer interpreted the following statement as too strong... “only 1 intervention developed specifically to target MI in Veterans/military service members...” It could be argued that many moral injury interventions (e.g., AD, IOK) were explicitly developed to target MI in Veterans or Service members or explicitly developed from an extant intervention (e.g., ACT-MI). Revising this sentence might be useful so that it is not interpreted that this intervention was the only treatment developed for moral injury. | We concur that our language was imprecise and incorrect in some places in this section (ie, we should not have stated that these studies ‘evaluated the efficacy of interventions’) and we have revised this section to improve clarity. We edited the table, which is now organized by study design and includes information on sample size, intervention format/delivery, comparator, etc. Please also see our response to comment #32.; Please see our response to comment #10 regarding the Building Spiritual Strength intervention.; We have revised the sentence regarding the MOVED intervention.