# ABBREVIATIONS TABLE

Abbreviation: Definition
3MDR: Multi-Modal Motion-Assisted Memory Desensitization and Reconsolidation
ACT-MI: Acceptable and Commitment Therapy for Moral Injury
AD: Adaptive Disclosure
AMPS-HCP: Accepting Moral Pain and Suffering for Healthcare Providers
BEP-MT: Brief Eclectic Psychotherapy for Moral Trauma
BMIS: Brief Moral Injury Screen
CBT: Cognitive behavioral therapy
CHAI: Comparative Health Assessment Interview
CPT: Cognitive processing therapy
HCW: Health care worker
EMIS: Expressions of Moral Injury Scale
IOK: Impact of Killing
KQ: Key question MC4 Mental Health Clinician Community Chaplain Collaboration
MI: Moral injury
MIDS: Moral Injury and Distress Scale
MIE: Morally injurious experience
MIES: Moral Injury Events Scale
MIG: Moral Injury Group
MIOS: Moral Injury Outcome Scale
MIS: Moral Injury Scale
MIQ: Moral Injury Questionnaire
MISS: Moral Injury Symptom Scale
MOVED: Moral Elevation Online Intervention for Veterans Experiencing Distress Related to
PTSD: and Moral Injury
NHRVS: National Health and Resilience in Veterans Study
PMIE: Potentially morally injurious event
PSP: Public safety personnel
QUIPS: Quality in Prognosis Studies tool
R&R: Restore and Rebuild
RCT: Randomized clinical trial
REAL: Reclaiming Experiences and Loss
SICPT: Spiritually Integrated Cognitive Processing Therapy
SR: Systematic review
STBs: Suicidal thoughts and behaviors
SUD: Substance use disorder TrIGR Trauma-Informed Guilt Reduction Therapy