# REFERENCES

1 US Burden of Disease Collaborators, Mokdad AH, Ballestros K, . The State of US Health, 1990-2016: Burden of Diseases, Injuries, and Risk Factors Among US States. Jama. 2018;319(14):1444–1472.29634829
2 Institute of Medicine (US) Committee on Advancing Pain Research, Care, and Education. Relieving Pain in America: A Blueprint for Transforming Prevention, Care, Education, and Research. Washington (DC): National Academies Press (US) 2011. https://www.ncbi.nlm.nih.gov/pubmed/22553896.
3 Gaskin DJ, Richard P. The economic costs of pain in the United States. J Pain. 2012;13(8):715–724.22607834
4 Zajacova A, Grol-Prokopczyk H, Zimmer Z. Pain Trends Among American Adults, 2002-2018: Patterns, Disparities, and Correlates. Demography. 2021;58(2):711–738.33834222
5 Banks SM, Kerns RD. Explaining high rates of depression in chronic pain: A diathesis-stress framework. Psychological Bulletin. 1996;119:95–110.
6 McWilliams LA, Cox BJ, Enns MW. Mood and anxiety disorders associated with chronic pain: an examination in a nationally representative sample. Pain. 2003;106(1-2):127–133.14581119
7 Racine M. Chronic pain and suicide risk: A comprehensive review. Prog Neuropsychopharmacol Biol Psychiatry. 2018;87(Pt B):269–280.28847525
8 Goulet JL, Kerns RD, Bair M, . The musculoskeletal diagnosis cohort: examining pain and pain care among veterans. Pain. 2016;157(8):1696–1703.27023420
9 Haskell SG, Ning Y, Krebs E, . Prevalence of painful musculoskeletal conditions in female and male veterans in 7 years after return from deployment in Operation Enduring Freedom/Operation Iraqi Freedom. Clin J Pain. 2012;28(2):163–167.21677563
10 Nahin RL. Severe Pain in Veterans: The Effect of Age and Sex, and Comparisons With the General Population. J Pain. 2017;18(3):247–254.27884688
11 VanDenKerkhof EG, Carley ME, Hopman WM, Ross-White A, Harrison MB. Prevalence of chronic pain and related risk factors in military veterans: a systematic review. JBI Database Syst Rev Implement Rep. 2014;12(10):152–186.
12 Dieleman JL, Cao J, Chapin A, . US Health Care Spending by Payer and Health Condition, 1996-2016. Jama. 2020;323(9):863–884.32125402
13 Kerns RD, Philip EJ, Lee AW, Rosenberger PH. Implementation of the veterans health administration national pain management strategy. Transl Behav Med. 2011;1(4):635–643.24073088
14 Yu W, Ravelo A, Wagner TH, . Prevalence and costs of chronic conditions in the VA health care system. Med Care Res Rev. 2003;60(3 Suppl):146S–167S.15095551
15 Buchbinder R, Underwood M, Hartvigsen J, Maher CG. The Lancet Series call to action to reduce low value care for low back pain: an update. Pain. 2020;161 Suppl 1:S57–S64.33090740
16 Veterans Health Administration. VHA National Pain Management Strategy [internet]. (2010) {cited 2014 Nov 14}.
17 Department of Veterans Affairs. VA/DoD Clinical practice guideline for diagnosis and treatment of low back pain [internet]. (2017) {cited 2020 May 12}.
18 CDC Guideline for Prescribing Opioids for Chronic Pain. Centers for Disease Control and Prevention;2016. https://www.cdc.gov/mmwr/volumes/65/rr/rr6501e1.htm.
19 VA/DoD Clinical Practice Guideline Work Group. Clinical Practice Guidelines for Managment of Opioid Therapy for Chronic Pain. Washington, D.C. 2017.
20 Becker WC, DeBar LL, Heapy AA, . A Research Agenda for Advancing Non-pharmacological Management of Chronic Musculoskeletal Pain: Findings from a VHA State-of-the-art Conference. J Gen Intern Med. 2018;33(Suppl 1):11–15.
21 Kligler B, Bair MJ, Banerjea R, . Clinical Policy Recommendations from the VHA State-of-the-Art Conference on Non-Pharmacological Approaches to Chronic Musculoskeletal Pain. J Gen Intern Med. 2018;33(Suppl 1):16–23.
22 Kerns RD, Krebs EE, Atkins D. Making Integrated Multimodal Pain Care a Reality: A Path Forward. J Gen Intern Med. 2018;33(Suppl 1):1–3.
23 Karlin BE, Cross G. From the laboratory to the therapy room: National dissemination and implementation of evidence-based psychotherapies in the U.S. Department of Veterans Affairs Health Care System. Am Psychol. 2014;69(1):19–33.24001035
24 Stewart MO, Karlin BE, Murphy JL, . National dissemination of cognitive-behavioral therapy for chronic pain in veterans: therapist and patient-level outcomes. Clin J Pain. 2015;31(8):722–729.25171637
25 Valenstein-Mah H, Greer N, McKenzie L, . Effectiveness of training methods for delivery of evidence-based psychotherapies: a systematic review. Implement Sci. 2020;15(1):40.32460866
26 Becker WC, Dorflinger L, Edmond SN, Islam L, Heapy AA, Fraenkel L. Barriers and facilitators to use of non-pharmacological treatments in chronic pain. BMC Fam Pract. 2017;18(1):41.28320337
27 Department of Veterans Affairs. VA/DoD Clinical Practice Guideline for the Management of Posttraumatic Stress Disorder and Acute Stress Disorder. https://www.healthquality.va.gov/guidelines/MH/ptsd/VADoDPTSDCPGFinal012418.pdf. Published 2017. Accessed August 24, 2021.
28 Department of Veterans Affairs. VA/DoD Clinical Practice Guideline for the Management of Major Depressive Disorder. https://www.healthquality.va.gov/guidelines/MH/mdd/VADoDMDDCPGFINAL82916.pdf. Published 2016. Accessed 2021, August 24.
29 Damschroder LJ, Aron DC, Keith RE, Kirsh SR, Alexander JA, Lowery JC. Fostering implementation of health services research findings into practice: a consolidated framework for advancing implementation science. Implement Sci. 2009;4:50.19664226
30 Damschroder LJ, Hagedorn HJ. A guiding framework and approach for implementation research in substance use disorders treatment. Psychol Addict Behav. 2011;25(2):194–205.21443291
31 RE-AIM Workgroup. https://www.re-aim.org/. Accessed August 24, 2021.
32 Glasgow RE, Harden SM, Gaglio B, . RE-AIM Planning and Evaluation Framework: Adapting to New Science and Practice With a 20-Year Review. Front Public Health. 2019;7:64.30984733
33 Powell BJ, McMillen JC, Proctor EK, . A compilation of strategies for implementing clinical innovations in health and mental health. Med Care Res Rev. 2012;69(2):123–157.22203646
34 Powell BJ, Waltz TJ, Chinman MJ, . A refined compilation of implementation strategies: results from the Expert Recommendations for Implementing Change (ERIC) project. Implement Sci. 2015;10:21.25889199
35 Wells GA, Shea B, O’Connell D, . The Newcastle-Ottawa Scale (NOS) for assessing the quality of nonrandomised studies in meta-analyses. Oxford; 2000
36 Singh J. Critical appraisal skills programme. Journal of pharmacology and Pharmacotherapeutics. 2013;4(1):76.
37 Murphy JL, Cordova MJ, Dedert EA. Cognitive behavioral therapy for chronic pain in veterans: Evidence for clinical effectiveness in a model program. Psychol Serv. 2020;28:28.
38 Brintz CE, Roth I, Faurot K, Rao S, Gaylord SA. Feasibility and Acceptability of an Abbreviated, Four-Week Mindfulness Program for Chronic Pain Management. Pain Med. 2020;21(11):2799–2810.32897319
39 Mun CJ, Otis JD, Concato J, . Further Examination of the Pain Stages of Change Questionnaires Among Chronic Low Back Pain Patients: Long-term Predictive Validity of Pretreatment and Posttreatment Change Scores and Stability of Posttreatment Scores. Clin J Pain. 2019;35(9):744–752.31149934
40 Fraser C, Beasley M, Macfarlane G, Lovell K. Telephone cognitive behavioural therapy to prevent the development of chronic widespread pain: a qualitative study of patient perspectives and treatment acceptability. BMC Musculoskelet Disord. 2019;20(1):198.31077168
41 Higgins DM, LaChappelle KM, Serowik KL, Driscoll MA, Lee A, Heapy AA. Predictors of Participation in a Nonpharmacological Intervention for Chronic Back Pain. Pain Med. 2018;19(suppl_1):S76–S83.30753730
42 Clarke SP, Poulis N, Moreton BJ, Walsh DA, Lincoln NB. Evaluation of a group acceptance commitment therapy intervention for people with knee or hip osteoarthritis: a pilot randomized controlled trial. Disabil Rehabil. 2017;39(7):663–670.27013221
43 George MC, Wongmek A, Kaku M, Nmashie A, Robinson-Papp J. A Mixed-Methods Pilot Study of Mindfulness-Based Stress Reduction for HIV-Associated Chronic Pain. Behav Med. 2017;43(2):108–119.26651852
44 Crisp CD, Hastings-Tolsma M, Jonscher KR. Mindfulness-Based Stress Reduction for Military Women With Chronic Pelvic Pain: A Feasibility Study. Mil Med. 2016;181(9):982–989.27612341
45 Bee P, McBeth J, MacFarlane GJ, Lovell K. Managing chronic widespread pain in primary care: a qualitative study of patient perspectives and implications for treatment delivery. BMC Musculoskelet Disord. 2016;17(1):354.27549811
46 Wetherell JL, Petkus AJ, Alonso-Fernandez M, Bower ES, Steiner AR, Afari N. Age moderates response to acceptance and commitment therapy vs cognitive behavioral therapy for chronic pain. Int J Geriatr Psychiatry. 2016;31(3):302–308.26216753
47 McCracken LM, Sato A, Wainwright D, House W, Taylor GJ. A feasibility study of brief group-based acceptance and commitment therapy for chronic pain in general practice: recruitment, attendance, and patient views. Prim Health Care Res Dev. 2014;15(3):312–323.23866920
48 Van Huet H, Innes E, Whiteford G. Living and doing with chronic pain: narratives of pain program participants. Disabil Rehabil. 2009;31(24):2031–2040.19874082
49 Patel S, Peacock SM, McKinley RK, Clark-Carter D, Watson PJ. GPs’ perceptions of the service needs of South Asian people with chronic pain: a qualitative enquiry. J Health Psychol. 2009;14(7):909–918.19786517
50 Heapy A, Otis J, Marcus KS, . Intersession coping skill practice mediates the relationship between readiness for self-management treatment and goal accomplishment. Pain. 2005;118(3):360–368.16289803
51 Kerns RD, Rosenberg R. Predicting responses to self-management treatments for chronic pain: application of the pain stages of change model. Pain. 2000;84(1):49–55.10601672
52 Koffel E, Vitiello MV, McCurry SM, Rybarczyk B, Von Korff M. Predictors of Adherence to Psychological Treatment for Insomnia and Pain: Analysis from a Randomized Trial. Clin J Pain. 2018;34(4):375–382.28915152
53 Thorn BE, Day MA, Burns J, . Randomized trial of group cognitive behavioral therapy compared with a pain education control for low-literacy rural people with chronic pain. Pain. 2011;152(12):2710–2720.21920668
54 Casey M-B, Murphy D, Neary R, Wade C, Hearty C, Doody C. Individuals perspectives related to acceptance, values and mindfulness following participation in an acceptance-based pain management programme. J Contextual Behav Sci. 2020;16:96–102.
55 Herman PM, Anderson ML, Sherman KJ, Balderson BH, Turner JA, Cherkin DC. Cost-effectiveness of Mindfulness-based Stress Reduction Versus Cognitive Behavioral Therapy or Usual Care Among Adults With Chronic Low Back Pain. Spine (Phila Pa 1976). 2017;42(20):1511–1520.28742756
56 Martinez ME, Kearney DJ, Simpson T, Felleman BI, Bernardi N, Sayre G. Challenges to Enrollment and Participation in Mindfulness-Based Stress Reduction Among Veterans: A Qualitative Study. J Altern Complement Med. 2015;21(7):409–421.26133205
57 Koffel E, Branson M, Amundson E, Wisdom JP. “Sign Me Up, I’m Ready!”: Helping Patients Prescribed Sleeping Medication Engage with Cognitive Behavioral Therapy for Insomnia (CBT-I). Behav Sleep Med. 2020;19(5):629–639.33063548
58 Song J, Garcia HA, Finley EP, Wiltsey Stirman S. Graduate training and provider concerns about distress and comprehension in PTSD treatment choice: A mediation analysis. Psychol Serv. 2020;07:07.
59 Koffel E, Hagedorn H. Provider perspectives of implementation of an evidence-based insomnia treatment in Veterans Affairs (VA) primary care: barriers, existing strategies, and future directions. Implement Sci Commun. 2020;1(1):107.33292865
60 Garcia HA, DeBeer BR, Mignogna J, Finley EP. Treatments Veterans Health Administration PTSD specialty program providers report their patients prefer: The role of training and theoretical orientation. Psychol Trauma. 2019;11(8):837–841.30816768
61 Doran JM, O’Shea M, Harpaz-Rotem I. In Their Own Words: Clinician Experiences and Challenges in Administering Evidence-Based Treatments for PTSD in the Veterans Health Administration. Psychiatr Q. 2019;90(1):11–27.30209719
62 Hundt NE, Helm A, Smith TL, Lamkin J, Cully JA, Stanley MA. Failure to engage: A qualitative study of veterans who decline evidence-based psychotherapies for PTSD. Psychol Serv. 2018;15(4):536–542.29265843
63 Finley EP, Noel PH, Lee S, . Psychotherapy practices for veterans with PTSD among community-based providers in Texas. Psychol Serv. 2018;15(4):442–452.28301173
64 Ulmer CS, Bosworth HB, Beckham JC, . Veterans Affairs Primary Care Provider Perceptions of Insomnia Treatment. J Clin Sleep Med. 2017;13(8):991–999.28728623
65 Sayer NA, Rosen CS, Bernardy NC, . Context Matters: Team and Organizational Factors Associated with Reach of Evidence-Based Psychotherapies for PTSD in the Veterans Health Administration. Adm Policy Ment Health. 2017;44(6):904–918.28597238
66 Richards LK, Bui E, Charney M, . Treating Veterans and Military Families: Evidence Based Practices and Training Needs Among Community Clinicians. Community Ment Health J. 2017;53(2):215–223.27155870
67 Osei-Bonsu PE, Bolton RE, Wiltsey Stirman S, Eisen SV, Herz L, Pellowe ME. Mental Health Providers’ Decision-Making Around the Implementation of Evidence-Based Treatment for PTSD. J Behav Health Serv Res. 2017;44(2):213–223.26743770
68 Lu MW, Plagge JM, Marsiglio MC, Dobscha SK. Clinician Documentation on Receipt of Trauma-Focused Evidence-Based Psychotherapies in a VA PTSD Clinic. J Behav Health Serv Res. 2016;43(1):71–87.24158464
69 Raza GT, Holohan DR. Clinical treatment selection for posttraumatic stress disorder: Suggestions for researchers and clinical trainers. Psychol Trauma. 2015;7(6):547–554.26053840
70 Hundt NE, Mott JM, Miles SR, Arney J, Cully JA, Stanley MA. Veterans’ perspectives on initiating evidence-based psychotherapy for posttraumatic stress disorder. Psychol Trauma. 2015;7(6):539–546.25915648
71 Finley EP, Garcia HA, Ketchum NS, . Utilization of evidence-based psychotherapies in Veterans Affairs posttraumatic stress disorder outpatient clinics. Psychol Serv. 2015;12(1):73–82.25419915
72 Ruzek JI, Eftekhari A, Rosen CS, . Factors related to clinician attitudes toward prolonged exposure therapy for PTSD. J Trauma Stress. 2014;27(4):423–429.25158635
73 Dedert EA, LoSavio ST, Wells SY, . Clinical effectiveness study of a treatment to prepare for trauma-focused evidence-based psychotherapies at a veterans affairs specialty posttraumatic stress disorder clinic. Psychol Serv. 2020;27:27.
74 Charney ME, Chow L, Jakubovic RJ, . Training community providers in evidence-based treatment for PTSD: Outcomes of a novel consultation program. Psychol Trauma. 2019;11(7):793–801.30688511
75 Possemato K, Johnson EM, Wray LO, Webster B, Stecker T. The implementation and testing of a referral management system to address barriers to treatment seeking among primary care veterans with PTSD. Psychol Serv. 2018;15(4):457–469.28714723
76 Rosen CS, Eftekhari A, Crowley JJ, . Maintenance and Reach of Exposure Psychotherapy for Posttraumatic Stress Disorder 18 Months After Training. J Trauma Stress. 2017;30(1):63–70.28103401
77 Crawford EF, Wolf GK, Kretzmer T, Dillon KH, Thors C, Vanderploeg RD. Patient, Therapist, and System Factors Influencing the Effectiveness of Prolonged Exposure for Veterans With Comorbid Posttraumatic Stress Disorder and Traumatic Brain Injury. J Nerv Ment Dis. 2017;205(2):140–146.27668355
78 Ruzek JI, Eftekhari A, Crowley J, Kuhn E, Karlin BE, Rosen CS. Post-training Beliefs, Intentions, and Use of Prolonged Exposure Therapy by Clinicians in the Veterans Health Administration. Adm Policy Ment Health. 2017;44(1):123–132.26487392
79 Drapkin ML, Wilbourne P, Manuel JK, Baer J, Karlin B, Raffa S. National Dissemination of Motivation Enhancement Therapy in the Veterans Health Administration: Training Program Design and Initial Outcomes. J Subst Abuse Treat. 2016;65:83–87.26951921
80 Ruzek JI, Eftekhari A, Rosen CS, . Effects of a comprehensive training program on clinician beliefs about and intention to use prolonged exposure therapy for PTSD. Psychol Trauma. 2016;8(3):348–355.26524541
81 Curran GM, Woo SM, Hepner KA, . Training Substance Use Disorder Counselors in Cognitive Behavioral Therapy for Depression: Development and Initial Exploration of an Online Training Program. J Subst Abuse Treat. 2015;58:33–42.26219680
82 Eftekhari A, Crowley JJ, Ruzek JI, Garvert DW, Karlin BE, Rosen CS. Training in the implementation of prolonged exposure therapy: provider correlates of treatment outcome. J Trauma Stress. 2015;28(1):65–68.25630446
83 Ruzek JI, Rosen RC, Garvert DW, . Online self-administered training of PTSD treatment providers in cognitive-behavioral intervention skills: results of a randomized controlled trial. J Trauma Stress. 2014;27(6):703–711.25522731
84 Walser RD, Karlin BE, Trockel M, Mazina B, Barr Taylor C. Training in and implementation of Acceptance and Commitment Therapy for depression in the Veterans Health Administration: therapist and patient outcomes. Behav Res Ther. 2013;51(9):555–563.23851161
85 Karlin BE, Trockel M, Taylor CB, Gimeno J, Manber R. National dissemination of cognitive behavioral therapy for insomnia in veterans: therapist- and patient-level outcomes. J Consult Clin Psychol. 2013;81(5):912–917.23586730
86 Mignogna J, Hundt NE, Kauth MR, . Implementing brief cognitive behavioral therapy in primary care: A pilot study. Transl Behav Med. 2014;4(2):175–183.24904701
87 Chard KM, Ricksecker EG, Healy ET, Karlin BE, Resick PA. Dissemination and experience with cognitive processing therapy. J Rehabil Res Dev. 2012;49(5):667–678.23015578
88 Cully JA, Teten AL, Benge JF, Sorocco KH, Kauth MR. Multidisciplinary cognitive-behavioral therapy training for the veterans affairs primary care setting. Prim Care Companion J Clin Psychiatry. 2010;12(3).
89 Kauth MR, Sullivan G, Blevins D, . Employing external facilitation to implement cognitive behavioral therapy in VA clinics: a pilot study. Implement Sci. 2010;5:75.20942951
90 Hepner KA, Hunter SB, Paddock SM, Zhou AJ, Watkins KE. Training addiction counselors to implement CBT for depression. Adm Policy Ment Health. 2011;38(4):313–323.21626444
91 Karlin BE, Ruzek JI, Chard KM, . Dissemination of evidence-based psychological treatments for posttraumatic stress disorder in the Veterans Health Administration. J Trauma Stress. 2010;23(6):663–673.21171126
92 Manber R, Trockel M, Batdorf W, . Lessons Learned from the National Dissemination of Cognitive Behavioral Therapy for Insomnia in the Veterans Health Administration. Sleep Med Clin. 2013;8(3):399–405.
93 Karlin BE, Brown GK, Trockel M, Cunning D, Zeiss AM, Taylor CB. National dissemination of cognitive behavioral therapy for depression in the Department of Veterans Affairs health care system: therapist and patient-level outcomes. J Consult Clin Psychol. 2012;80(5):707–718.22823859
94 Clark DM, Layard R, Smithies R, Richards DA, Suckling R, Wright B. Improving access to psychological therapy: Initial evaluation of two UK demonstration sites. Behav Res Ther. 2009;47(11):910–920.19647230
95 Landes SJ, Matthieu MM, Smith BN, Rodriguez AL. Strategies to overcome barriers to implementing dialectical behavior therapy in the department of veterans affairs: Perspectives from a national program evaluation. the Behavior Therapist. 2017;40(7):251–255.
96 Kauth MR, Adler G, McCandless SJ, Leopolous WS. Embedding new clinical practices: the role of facilitation in enhancing web-based training for mental health providers. The Journal of Mental Health Training, Education and Practice. 2017;12(1):24–32.
97 Amodeo M, Lundgren L, Cohen A, . Barriers to implementing evidence-based practices in addiction treatment programs: comparing staff reports on Motivational Interviewing, Adolescent Community Reinforcement Approach, Assertive Community Treatment, and Cognitive-behavioral Therapy. Eval Program Plann. 2011;34(4):382–389.21420171
98 Kyrios M, Moulding R, Jones B. Obsessive compulsive disorder: integration of cognitive-behaviour therapy and clinical psychology care into the primary care context. Aust J Prim Health. 2010;16(2):167–173.21128579
99 Sommerfeld DH, Granholm E, Holden J, . Concept mapping study of stakeholder perceptions of implementation of cognitive-behavioral social skills training on assertive community treatment teams. Psychol Serv. 2019;18(1):33–41.30855157
100 DePhilippis D, Petry NM, Bonn-Miller MO, Rosenbach SB, McKay JR. The national implementation of Contingency Management (CM) in the Department of Veterans Affairs: Attendance at CM sessions and substance use outcomes. Drug Alcohol Depend. 2018;185:367–373.29524874
101 Garcia HA, Mignogna J, DeBeer BR, Song J, Haro EK, Finley EP. Provider factors predict use of evidence-based psychotherapies in veterans affairs posttraumatic stress disorder specialty programs: The role of profession, theoretical orientation, and training. Traumatology. 2020;26(2):227–234.
102 Hamblen JL, Bernardy NC, Sherrieb K, . VA PTSD clinic director perspectives: How perceptions of readiness influence delivery of evidence-based PTSD treatment. Professional Psychology: Research and Practice. 2015;46(2):90–96.
103 Weathers FW, Litz BT, Herman DS, Huska JA, Keane TM. The PTSD Checklist (PCL): Reliability, validity, and diagnostic utility. Paper presented at: annual convention of the international society for traumatic stress studies, San Antonio, TX 1993.
104 Blanchard EB, Jones-Alexander J, Buckley TC, Forneris CA. Psychometric properties of the PTSD Checklist (PCL). Behav Res Ther. 1996;34(8):669–673.8870294
105 Smarr KL, Keefer AL. Measures of depression and depressive symptoms: Beck Depression Inventory-II (BDI-II), Center for Epidemiologic Studies Depression Scale (CES-D), Geriatric Depression Scale (GDS), Hospital Anxiety and Depression Scale (HADS), and Patient Health Questionnaire-9 (PHQ-9). Arthritis Care Res (Hoboken). 2011;63 Suppl 11(S11):S454–466.22588766
106 Department of Veterans Affairs National Center for PTSD. PTSD Treatment Decision Aid. https://www.ptsd.va.gov/apps/decisionaid/. Accessed August 30, 2021.
107 Department of Veterans Affairs. Cognitive behavioral therpay for depression. https://www.mentalhealth.va.gov/docs/cbt_brochure.pdf
108 Department of Veterans Affairs. Cognitive behavioral therapy for chronic pain. https://www.va.gov/PAINMANAGEMENT/CBT_CP/docs/CBT-CP-PatientBrochure-PrintVersion.pdf# (https://www.va.gov/PAINMANAGEMENT/CBT_CP/docs/CBT-CP-PatientBrochure-PrintVersion.pdf)
109 Li H, Glecia A, Kent-Wilkinson A, Leidl D, Kleib M, Risling T. Transition of Mental Health Service Delivery to Telepsychiatry in Response to COVID-19: A Literature Review. Psychiatr Q. 2021:1–17.
110 Cigrang JA, Rauch SA, Avila LL, . Treatment of active-duty military with PTSD in primary care: Early findings. Psychol Serv. 2011;8(2):104.
111 Cigrang JA, Rauch SA, Mintz J, . Treatment of active duty military with PTSD in primary care: A follow-up report. J Anxiety Disord. 2015;36:110–114.26519833
112 Bramoweth AD, Lederer LG, Youk AO, Germain A, Chinman MJ. Brief Behavioral Treatment for Insomnia vs Cognitive Behavioral Therapy for Insomnia: Results of a Randomized Noninferiority Clinical Trial Among Veterans. Behav Ther. 2020;51(4):535–547.32586428
113 Luedtke A, Kessler RC. New Directions in Research on Heterogeneity of Treatment Effects for Major Depression. JAMA Psychiatry. 2021;78(5):478–480.33595616
114 Kent DM, Rothwell PM, Ioannidis JP, Altman DG, Hayward RA. Assessing and reporting heterogeneity in treatment effects in clinical trials: a proposal. Trials. 2010;11(1):85.20704705
115 Kent DM, Paulus JK, Van Klaveren D, . The predictive approaches to treatment effect heterogeneity (PATH) statement. Ann Intern Med. 2020;172(1):35–45.31711134
116 Solomonov N, Lee J, Banerjee S, . Modifiable predictors of nonresponse to psychotherapies for late-life depression with executive dysfunction: a machine learning approach. Mol Psychiatry. 2020:1–9.
117 Kaiser T, Volkmann C, Volkmann A, Karyotaki E, Cuijpers P, Brakemeier E-L. Heterogeneity of treatment effects in trials on psychotherapy of depression. 2020.
118 Kashner TM, Henley SS, Golden RM, Zhou X-H. Making causal inferences about treatment effect sizes from observational datasets. Biostatistics & Epidemiology. 2020;4(1):48–83.
119 Van Dyke BP, Newman AK, Morais CA, Burns JW, Eyer JC, Thorn BE. Heterogeneity of Treatment Effects in a Randomized Trial of Literacy-Adapted Group Cognitive-Behavioral Therapy, Pain Psychoeducation, and Usual Medical Care for Multiply Disadvantaged Patients With Chronic Pain. J Pain. 2019;20(10):1236–1248.31022555
120 Bartz D, Chitnis T, Kaiser UB, . Clinical advances in sex-and gender-informed medicine to improve the health of all: a review. JAMA Intern Med. 2020;180(4):574–583.32040165
121 Canadian Institutes of Health Research. Online Training Modules: Integrating Sex & Gender in Health Research. https://cihr-irsc.gc.ca/e/49347.html. Accessed August 30, 2021.
122 Heidari S, Babor TF, De Castro P, Tort S, Curno M. Sex and gender equity in research: rationale for the SAGER guidelines and recommended use. Research integrity and peer review. 2016;1(1):1–9.27158530
123 Kabat-Zinn J. An outpatient program in behavioral medicine for chronic pain patients based on the practice of mindfulness meditation: theoretical considerations and preliminary results. Gen Hosp Psychiatry. 1982;4(1):33–47.7042457
124 Peterson LG, Pbert L. Effectiveness of a meditation-based stress reduction program in the treatment of anxiety disorders. Am J Psychiatry. 1992;149(7):936–943.1609875
125 Anthes E. Mental health: There’s an app for that. Nature. 2016;532(7597):20–23.27078548
126 Guo C, Ashrafian H, Ghafur S, Fontana G, Gardner C, Prime M. Challenges for the evaluation of digital health solutions-A call for innovative evidence generation approaches. NPJ Digit Med. 2020;3(1):110.32904379
127 Heapy AA, Higgins DM, Goulet JL, . Interactive Voice Response-Based Self-management for Chronic Back Pain: The COPES Noninferiority Randomized Trial. JAMA Intern Med. 2017;177(6):765–773.28384682
128 Bee PE, Bower P, Lovell K, . Psychotherapy mediated by remote communication technologies: a meta-analytic review. BMC Psychiatry. 2008;8(1):60.18647396
129 Bramoweth AD, Germain A, Youk AO, Rodriguez KL, Chinman MJ. A hybrid type I trial to increase Veterans’ access to insomnia care: study protocol for a randomized controlled trial. Trials. 2018;19(1):73.29373993
130 McCrae CS, Bramoweth AD, Williams J, Roth A, Mosti C. Impact of brief cognitive behavioral treatment for insomnia on health care utilization and costs. J Clin Sleep Med. 2014;10(2):127–135.24532995
131 Germain A, Markwald RR, King E, . Enhancing behavioral sleep care with digital technology: study protocol for a hybrid type 3 implementation-effectiveness randomized trial. Trials. 2021;22(1):46.33430955
132 Troxel WM, Germain A, Buysse DJ. Clinical management of insomnia with brief behavioral treatment (BBTI). Behav Sleep Med. 2012;10(4):266–279.22946736