# ACKNOWLEDGMENTS

This topic was developed in response to a nomination by the Pain/Opioid Consortium of Research (CORE), funded by VA Health Services Research and Development (HSR&D). The scope was further developed with input from the topic nominators (ie, Operational Partners), the ESP Coordinating Center, the review team, and the Technical Expert Panel (TEP).

In designing the study questions and methodology at the outset of this report, the ESP consulted several technical and content experts. Broad expertise and perspectives were sought. Divergent and conflicting opinions are common and perceived as healthy scientific discourse that results in a thoughtful, relevant systematic review. Therefore, in the end, study questions, design, methodologic approaches, and/or conclusions do not necessarily represent the views of individual technical and content experts.

The authors gratefully acknowledge the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who have requested the report to inform decision-making. They recommend TEP participants; assure VA relevance; help develop and approve final project scope and timeframe for completion; provide feedback on draft report; and provide consultation on strategies for dissemination of the report to field and relevant groups.

- Alicia Heapy, PhD
  Associate Director, Pain Research, Informatics, Multimorbidities, and Education (PRIME) Center
  Principal Investigator, VA HSR&D Pain/Opioid Consortium for Research (CORE)
  VA Connecticut Healthcare System
- William Becker, MD
  Principal Investigator, VA HSR&D Pain/Opioid Consortium for Research (CORE)
  VA Connecticut Healthcare System
- Erin Krebs, MD, MPH
  Principal Investigator, VA HSR&D Pain/Opioid Consortium for Research (CORE)
  Minneapolis VA Healthcare System

## Technical Expert Panel (TEP)

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Jennifer Murphy, PhD
  Director of Behavioral Pain Medicine, Pain Management and Opioid Safety Program Office, VA
  Specialty Care Services
  Tampa VAMC
- Robert Kerns, PhD
  Director, Pain Research, Informatics, Medical Comorbidities, and Education (PRIME) Center
  VA Connecticut Healthcare System
  Professor of Psychiatry, Neurology, and Psychology, Yale University
- Bradley Karlin, PhD
  Vice President and Chief of Mental Health and Aging, Education Development Center, Inc.
  Kaiser Permanente Institute for Health Policy
- Amanda Midboe, PhD
  Core Investigator, Center for Innovation to Implementation
  Palo Alto VA Healthcare System
- Kristine Day, PhD
  VA National Evidence-Based Psychotherapy Program Manager, Office of Mental Health and Suicide Prevention
- Hani Shabana, PhD
  VA CBT-Chronic Pain Training Program Coordinator, Office of Mental Health and Suicide Prevention
  VAMC Salem, VA

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence. Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center and the ESP Center work to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.