# SUMMARY AND DISCUSSION

## SUMMARY OF KEY FINDINGS

In this systematic review, we sought evidence relevant to implementation of EBPs for chronic pain and chronic mental health conditions, focusing on 1) barriers and facilitators at the patient, provider, and system levels; and 2) results of various implementation strategies aimed at promoting uptake of and engagement with EBPs. We identified 67 eligible articles, with most of these addressing CBT or CPT/PE. Additionally, the vast majority of studies were conducted in VHA, with the exception of those for MBSR and ACT, which occurred in non-VA US community settings or non-US countries, respectively. Key findings include:

- Evidence on CBT for chronic pain mostly addressed individual therapy (via telehealth or in person), while MBSR and ACT occurred in group settings in person.
- Barriers to CBT for chronic pain included cultural, communication, and logistical barriers; mismatch between patient knowledge and beliefs about pain and EBP principles; logistical conflicts for patients; and patient attributes including high pain-related interference.
- Facilitators of CBT for chronic pain included positive patient-therapist dynamics; good match between patient knowledge and beliefs about pain and EBP principles; patient readiness for change; and telehealth availability.
- One article showed that CBT and MBSR for chronic pain were cost-effective for improving quality of life.
- Barriers to MBSR and ACT for chronic pain included mismatch between patient knowledge and beliefs about pain and EBP principles; the physical discomfort of being seated for sessions; and logistical conflicts.
- Facilitators of MBSR and ACT for chronic pain settings included positive group dynamics and good match between patient knowledge and beliefs about pain and EBP principles.
- Barriers of CBT for chronic mental health conditions included lack of resources and referring provider knowledge about CBT, and patient factors (eg, comorbidities, cultural and communication barriers, transportation barriers).
- Facilitators of CBT for chronic mental health conditions included: scalability and convenience of CBT tools and resources; local champions and leadership support; and strong networks and communication across clinics and teams.
- Barriers to CPT/PE in VHA settings included inflexibility of treatment protocols, complex referral processes, patient complexity and competing needs, and negative perceptions of VHA care.
- Facilitators of CPT/PE in VHA settings included strong support for training, perceived effectiveness for patients and benefits for clinics, and positive patient experiences and relationships with providers.
- In non-VA community settings, mental health providers generally had low concern for barriers, but few had been trained in CPT/PE.
- Barriers for CBSST included workload and staffing challenges. Facilitators were supportive external policies and resources, leadership engagement, training support and materials, networks and communications among providers, and positive provider perceptions and experience.
- Facilitators for DBT included leadership engagement and training resources, but providers had difficulty completing online training during working hours.
- National or local VHA training initiatives for CBT, ACT, and CPT/PE involved training/education, facilitation, and audit/feedback.
- Large numbers of mental health providers have completed VHA national training programs for EBPs, leading to improved provider perceptions, self-efficacy, and providers skills for delivering EBPs, but persistent barriers limit reach and adoption.
- VHA implementation of CBT for chronic pain and chronic mental health conditions, ACT for depression, and CPT/PE reduced symptoms and improved quality of life for patients.
- Over two-thirds of VHA SUD treatment clinics (that participated in national VHA initiative) implemented standard CM, with most operational 40 months post-training.
- Non-VA providers who underwent a training program for CPT/PE reported higher self-efficacy post-training, and use of CPT/PE at 3 (58%) and 6 months (64%).

Results regarding barriers and facilitators to uptake of CBT, MBSR, and ACT for chronic pain mainly addressed patient-level factors. We classified these as pertaining to the CFIR domain of Outer Setting, including common subdomains Patient Needs and Resources and Patient Knowledge and Beliefs. A commonly perceived barrier to uptake of all 3 EBPs was mismatch between patients’ pain beliefs and experiences and patients’ perceptions of core EBP concepts, while a good match was a facilitator. Logistical barriers were common for patients within all 3 EBPs, and telehealth overcame some of these barriers within tCBT. High pain-related interference was associated with poor adherence to some CBT and MBSR interventions. Patient demographics did not consistently predict adherence to CBT, MBSR, or ACT; however, 1 study developing group CBT for a rural, low-literacy population with chronic pain found that lower educational attainment was associated with both declining to participate and not completing the intervention. Only 2 articles addressed barriers and facilitators at the provider or system level: 1 cost-effectiveness analysis of MBSR and CBT versus UC and 1 analysis of GP interviews about chronic pain treatments including CBT. Definitions of chronic pain and inclusion/exclusion criteria varied across studies.

Evidence on barriers and facilitators for EBPs for chronic mental health conditions addressed patient, provider, and system factors, and pertained to a variety of CFIR domains. Shared barriers across these EBPs included workload and scheduling challenges for providers, lack of educational resources and training for referring providers, transportation needs and competing responsibilities for patients, and variable patient buy-in to treatment rationale. Shared facilitators were leadership engagement, training and treatment delivery resources, communications and networks for continuing provider education, and positive patient-provider relationships. It is important to note that these psychotherapy approaches are distinct from those employed for chronic pain management and focus on independent non-pain conditions. For example, CPT/PE focuses on trauma processing and CBT-I focuses on regularizing the sleep-wake cycle. Although it is likely that some barriers and facilitators generalize to chronic pain treatments, especially at provider and system levels, therapies for non-pain conditions may have unique challenges to implementation relative to EBPs for chronic pain.

VHA national training programs for a variety of EBPs increased provider self-efficacy and improved perceptions of EBP, particularly after completion of expert consultation, suggesting that there is additional benefit to audit and feedback. However, it is unclear the degree to which these initiatives increased uptake by appropriate patients and overall adoption by providers. It is also unclear whether external facilitation has added benefits. National VHA training initiatives provided centralized facilitation resources, including salary support for clinicians; patient-facing EBP materials and tools; and coordination and organizational support for training and problem-solving. It is unclear to what degree these resources enhanced adoption in addition to training and audit/feedback. Only 1 small study examined external facilitation independently of training, finding no added benefit for facilitated participants in terms of specific CBT knowledge and skills at 3 months post-workshop.

In general, VHA training programs for a variety of EBPs led to sustained effects on provider use of EBPs but with persistent concerns about level of uptake by patients who would benefit from these treatments. Across EBPs, there was variable contribution of patient barriers to reach (eg, lack of acceptability for patients) and provider barriers to adoption (eg, workload and scheduling challenges) that resulted in lower numbers of patients receiving EBPs. In some cases, there were likely interactions between patient and provider factors, where lower patient acceptability may have contributed to provider concerns regarding appropriateness or prioritization of certain EBPs. In other cases, lower levels of uptake may primarily have been due to lack of capacity for treatment delivery (eg, competing work demands for providers).

These results indicate that VHA national initiatives for EBPs have largely not focused on patient barriers and facilitators for uptake, or addressed potential heterogeneity in treatment response due to patient factors. A notable exception may be the interactive decision aid for PTSD (developed by the VA National Center for PTSD) that provides tailored treatment information and recommendations according to patient preferences and values.^106^ Additionally, there may be important tradeoffs to consider for options that address transportation barriers and competing responsibilities during the workday. For example, EBPs may be delivered via telephone or videoconferencing, to address transportation and time barriers, but this may negatively impact development of therapeutic alliance due to lack of in-person contact. Moreover, our results show that different patients may have strong and opposing preferences for formats (eg, telephone vs in-person sessions) or communication styles (eg, group facilitators maintaining structured control vs letting participants tell their own stories at length), which may be difficult for mental health clinics and providers to accommodate. It also remains unclear how options in EBP format or tailoring may improve treatment uptake and response.

Finally, our results showed variation in the formats and duration of certain EBPs. These differences likely reflect consideration of resources (space and provider capacity) and patient needs (extending sessions to account for patient progress). Such variability present substantial challenges in distinguishing the “core” of essential treatment characteristics from the “adaptable periphery” of elements that may be modified without threatening efficacy. Additionally, some implementation strategies aimed at increasing patient readiness for EBPs (eg, patient preparatory groups) may constitute distinctive treatments that warrant high-quality studies examining efficacy along with implementation outcomes. However, our results also suggest that efforts to clearly define EBP content and duration may lead to greater provider barriers to adoption of EBPs, due to higher perceived inflexibility and lack of adaptability.

## IMPLICATIONS FOR VA POLICY

VHA has made substantial investments in providing high-quality EBPs and remains committed to improving access to mental health services for Veterans. Our results indicate that VHA national training programs for EBPs have greatly increased the number of mental health providers who are prepared to deliver EBPs. However, our results on persistent barriers to uptake suggest that VHA national initiatives for EBPs should focus on additional avenues to further increase the reach of these therapies. First, there may be value in coordinated efforts to address patient-level barriers to uptake. While VHA has developed patient-facing EBP educational materials, these may not adequately address patient concerns; for the most part, these materials generally describe treatments for various conditions and are not otherwise tailored to patient needs or goals.^107,108^ To be successful, informational materials may need to be tailored to address specific concerns and optimized for dissemination to particular groups. Thus, development and dissemination of improved patient-facing resources may help increase patient awareness and buy-in.

Additionally, national VHA programs may consider guidance or support for delivery formats or options beyond in-person meetings during the workday. During the COVID-19 pandemic, there were rapid shifts to EBPs delivered via telehealth,^109^ including for VHA mental health services. VHA has started to evaluate the current experience with EBP via telehealth, as compared with in-person treatment (VHA mental health leadership, personal communication, 2021). Hopefully, these evaluations will deepen our understanding of the impacts and trade-offs between different delivery formats, thereby helping to inform best practices that can be disseminated across VHA facilities.

It may also be important for VHA initiatives to provide additional support and information for facilities regarding how to organize and integrate mental health services. For example, how should local leadership evaluate their capacity for delivering various EBPs and balance competing demands and priorities between EBPs? There may also be opportunities to improve efficiency and enhance uptake by integrating mental health services with primary care or other specialty care services. Efforts to simplify referral pathways and streamline treatments for mental and physical health may simultaneously reduce barriers for referring providers and address patient reticence. For example, we identified 1 article reporting the development of new referral processes within primary care to streamline next steps for patients and providers and increase patients’ positive attitudes towards EBPs for PTSD. Modified, brief therapy protocols for providing treatment in primary care for anxiety and depression, PTSD, and insomnia, have shown promise, although additional work is needed to establish efficacy.^86,110–112^ Given the potential diversity in local resources, needs, and priorities, national VHA initiatives may consider providing guidance on performing local needs assessments and matching strategies or resources to those results (eg, strategies to enhance leadership engagement, train local champions, and facilitate communication across primary care and specialty clinics).

Therefore, we suggest the following:

- Develop and disseminate tailored patient-facing resources to increase awareness and buy-in.
- Evaluate outcomes for alternative EBP delivery formats (individual vs group therapy, brief vs longer treatment duration), and when appropriate, support increased options for session formats.
- Evaluate outcomes for telehealth versus in person EBP delivery, and where appropriate, support increased options for both formats and scheduling flexibility.
- Evaluate and support strategies for streamlining EBP referral processes.
- Provide guidance on local needs assessment for implementation readiness and matching of strategies and resources.

## RESEARCH GAPS/FUTURE RESEARCH

There was very limited evidence on provider- and system-level barriers and facilitators for EBPs for chronic pain. Because we anticipated this potential gap, we undertook a broader review that examined evidence for provider and system factors for EBPs for chronic mental health conditions. However, there are likely some factors that are unique to EBPs for chronic pain, including provider views about effectiveness or acceptability of EBPs, availability of resources, and interactions with other VHA initiatives (eg, regarding opioid safety). These factors may contribute to provider referral patterns that are distinct from EBPs for chronic mental health conditions. We recommend further study of provider- and system-level barriers and facilitators to EBP for chronic pain. Additionally, most analyses of patient-level barriers and facilitators for EBPs for chronic pain, particularly for ACT and CBT, were conducted within effectiveness RCTs rather than in non-research clinical contexts. As barriers and facilitators to adherence likely vary meaningfully between clinical trials and clinical practice, we recommend further study of barriers and facilitators to EBPs for chronic pain within clinical practice settings.

Results related to EBPs for chronic pain suggest there may be substantial heterogeneity in relationships of patient-level factors to treatment uptake. Some of these, such as patient beliefs about therapy and about pain, may also be related to treatment effects, and we lack evidence on how EBPs may be tailored to patient-level factors to improve both uptake and outcomes. Heterogeneity in relationships of patient-level factors to treatment effects is also evident within EBPs for chronic pain and is becoming a methodological focus of future pain treatment research and of behavioral health research in general.^113–119^ More systematic assessment of heterogeneity of treatment effects as well as of treatment uptake may identify specific patient-level targets suitable for future implementation or hybrid effectiveness-implementation work. More research is also needed to identify and clarify cultural and social factors that may mitigate both effectiveness and patient adherence for EBPs for chronic pain, in order to inform culturally and socially relevant adaptations where needed. While quantitative analyses using electronic medical record data on patient “race” and “ethnicity” did not identify barriers to adherence, these indicators are of unclear quality and are poor proxies for patient cultural and social experience. Similarly, while quantitative analyses including either “sex” or “gender” did not identify barriers to adherence, clear variable definitions were not provided, so it is unclear whether “sex” or “gender” would accurately apply: an important distinction that affects interpretation of results.^120–122^ No studies explored roles of culture, race, sex, gender, or social factors in patients’ views or experiences of EBPs.

The vast majority of results on implementation efforts for EBPs were from VHA national training programs. These included education/training, audit/feedback, and external facilitation. While some results indicated that audit/feedback may be important for improving provider perceptions and skills, there was a lack of evidence evaluating the impact of external feedback. This may be especially crucial to understand for healthcare systems that have fewer resources than VHA and thus lack capacity for external facilitation on the same scale as VHA initiatives. Additionally, evaluations of VHA national training programs generally did not address reach (ie, the proportion and representativeness of patients who initiated or completed EBPs). Although reach may be challenging to measure, even for large integrated systems such as VHA, it is nevertheless critical to assess how many (and which) patients benefit from treatments. The ultimate metric for evaluating success of any implementation strategy must be whether it increased the reach of effective treatments, leading to better outcomes for more individuals. Particularly for chronic pain treatments, evaluation of reach across a variety of clinical settings should occur in conjunction with further research into provider- and system-level factors that contribute to differences in referral rates and treatment engagement.

Few studies utilized comprehensive theoretical frameworks for assessing barriers/facilitators, examining process of change in implementation trials, and reporting outcomes. Future implementation work should be guided by theoretical domains linking barriers to strategies, examining processes of change, and comprehensively evaluating outcomes in key domains. The new CFIR subdomains that arose from this work, including Patient Knowledge and Beliefs, Other Patient Attributes, Group Dynamics, and Patient-Therapist Dynamics, may be helpful in future efforts to examine patient-level barriers to engagement with EBPs.

No studies analyzed barriers, facilitators, or implementation strategies for group CBT for chronic pain, individual ACT for chronic pain, or individual MBSR for chronic pain. While MBSR was developed in a group format for chronic pain as well as for other mental health conditions,^123,124^ both CBT and ACT are provided regularly in both group and individual formats. Future research should analyze both efficacy and implementation for group CBT formats and individual ACT formats as treatments for chronic pain.

Finally, future research is needed to evaluate asynchronous digital and brief formats as possible avenues to increase reach of EBPs by addressing patient-level barriers (eg, transportation, time, and geographical distance). Ongoing work shows promise in establishing the efficacy and effectiveness of asynchronous digital formats for delivering EBP. Although these digital interventions may eliminate some barriers, it is currently unclear if they can consistently achieve the same benefits in symptom reduction and quality of life as traditional synchronous EBPs.^41,125–128^ Furthermore, examination of implementation outcomes will also be needed to identify potentially unique barriers for these interventions. Similarly, brief formats for EBPs are another promising strategy for enhancing reach and reducing patient and provider barriers. In the case of CBT-I, initial work has demonstrated effectiveness of a brief format, while ongoing studies are exploring the effects on reach, adoption, implementation, and maintenance.^112,129–132^

Therefore, we recommend the following for future research:

- Examine provider- and system-level barriers and facilitators for CBT, MBSR, and ACT for chronic pain using comprehensive frameworks and in clinical practice settings.
- Evaluate patient-level factors contributing to heterogeneity of treatment effects and treatment uptake for EBPs for chronic pain and identify targets for future effectiveness and implementation work.
- Evaluate patient-level sociocultural and demographic factors including sex, gender, race and ethnicity accurately and with clear analytic purpose, recognizing the importance of clear definitions consistent with data analyzed and the roles of demographic indicators as limited proxies for sociocultural experience.
- Evaluate the added value of external facilitation when used with education/training and audit/feedback.
- Describe reach for EBPs associated with implementation strategies, such as VHA national training programs for EBPs.
- Use implementation frameworks to guide future evaluations of barriers and facilitators, processes of change, and outcomes in key domains.
- Evaluate efficacy and implementation outcomes for group CBT formats and individual ACT formats as treatments for chronic pain.
- Evaluate efficacy and implementation outcomes for asynchronous digital and brief formats for various EBPs.

## LIMITATIONS

We aimed to be inclusive in examining evidence on barriers, facilitators, and implementation outcomes for a broad range of EBPs for chronic mental health conditions. But given our focus on those results that would be most applicable to VHA settings and the implementation of EBPs for chronic pain, we included EBPs that were recommended for eligible conditions and were available in VHA. Thus, we did not include EBPs that may be recommended for particular conditions but were not accessible in VHA. We also sought to focus on provider- and system-level barriers and facilitators for implementation of EBPs for chronic mental health conditions, due to the greater applicability of such results for implementation of EBPs for chronic pain. However, results often involved interrelationships between patient, provider, and system factors.

Additionally, some patient factors appeared consistent across the types of EBPs, such as transportation barriers and competing work and family responsibilities. Therefore, we elected to include results on patient-level barriers and facilitators for EBPs for chronic mental health conditions. We limited eligibility to English-language studies conducted in the US or in a small set of non-US countries with comparable economic, cultural, and public health contexts (Canada, UK, Ireland, and Australia). Although evidence from excluded countries would likely have been less applicable, it is possible that it may have provided some relevant information.

## CONCLUSIONS

Studies of barriers and facilitators to EBPs for chronic pain focused largely on patient-level findings, with little provider- or system-level information. VHA training programs for a variety of EBPs for chronic pain and mental health conditions led to sustained effects on provider use of EBPs but with persistent concerns about level of uptake by patients who would benefit from these treatments, and maintenance of effects for providers who deliver these treatments. Shared barriers across EBPs included workload and scheduling challenges for providers; lack of educational resources and training for referring providers; transportation needs and competing responsibilities for patients; and variable patient buy-in to EBP rationale. Shared facilitators were leadership engagement; training and treatment delivery resources; communications and networks for continuing provider education; and positive patient-provider relationships. Future work is needed to explore heterogeneity of treatment effects within EBPs for chronic pain, as well as provider- and system-level barriers and facilitators for EBPs for chronic pain. Additionally, VHA national initiatives for EBPs have largely not focused on patient factors affecting uptake and heterogeneity in treatment. It may be useful to develop and disseminate patient educational materials to increase awareness and acceptability of EBPs. It will also be important to evaluate outcomes for alternative EBP delivery formats and modalities. At a provider and system level, VHA facilities may benefit from strategies to streamline EBP referral processes, and guidance for conducting local needs assessment on implementation readiness and matching of strategies and resources.