# METHODS

The protocol was registered in PROSPERO: CRD42021252038.

## TOPIC DEVELOPMENT

Collaboratively with representatives from the VA Pain/Opioid CORE and an advisory panel of experts, we defined the scope, formulated key questions (KQ), and determined the eligibility criteria. Because the goal of this evidence synthesis is to support implementation of EBPs for chronic pain, we first focused on those psychotherapies with the strongest evidence base for efficacy in chronic pain treatment, CBT, ACT, and MBSR.^20,21^ Additionally, we also considered implementation evidence for those EBPs recommended by clinical guidelines for various mental health conditions (eg, depression, PTSD^27,28^) and readily available within VHA. For implementation of EBPs for non-pain conditions, we focused on provider- and system-level barriers and facilitators because these would likely be more applicable to improving implementation of psychotherapies for pain. We considered patient factors in a non-pain context more likely to be distinct from and less applicable to implementation of chronic pain treatments. Additionally, in order to identify evidence with greater applicability for Veterans enrolled in VHA, we sought studies that examined barriers and facilitators, or evaluated implementation strategies, in large integrated health care delivery systems. We expanded the setting beyond the US to include Canada, the UK, Ireland, and Australia for 2 reasons—1) existence of integrated health systems with qualities similar to VHA; and 2) comparable economic, cultural, and public health contexts, including predominant use of English.

## KEY QUESTIONS

KQ1 For cognitive behavioral therapy, acceptance and commitment therapy, and mindfulness-based therapy used to treat adults with chronic pain:
  a) What are the patient-, provider-, and system-level barriers and facilitators for treatment uptake?
  b) What is the effect of implementation strategies to increase uptake of these treatments?
KQ2 For evidence-based psychotherapies and mindfulness-based interventions used in integrated delivery systems to treat adults with chronic mental health conditions:
  a) What are the provider- and system-level barriers and facilitators to treatment uptake?
  b) What is the effect of implementation strategies to increase uptake of these treatments?

## SEARCH STRATEGY

We searched the following databases from inception through March 2021: MEDLINE, Embase, PsycINFO, and CINAHL. Search terms included MeSH and free text for: EBP names (eg, CBT, ACT, and MBSR), chronic pain, integrated delivery systems and Veterans (Appendix A). We also sought relevant systematic reviews from the Agency for Healthcare Research and Quality (AHRQ) Evidence-based Practice Center (EPC) reports and VA ESP reports; we hand-searched relevant reviews for potentially eligible studies. Our expert advisory panel also provided referrals.

## SCREENING AND SELECTION OF ELIGIBLE STUDIES

Duplicate results were removed and abstracts were screened using DistillerSR (Evidence Partners, Ottawa, Canada). Prespecified eligibility criteria (Appendix B) included: outpatient treatment of adults with chronic pain or chronic mental health condition; EBPs used for chronic pain or chronic mental health conditions (eg, CBT, ACT, MBSR, Prolonged Exposure Therapy [PE], and Cognitive Processing Therapy [CPT]); examination of barriers and facilitators, and/or evaluation of implementation strategies; and conducted in the US, United Kingdom (UK), Ireland, Canada, or Australia. Exclusion of abstracts required agreement of 2 reviewers. Included abstracts underwent full-text review by 2 individuals, with eligibility decisions requiring consensus of both reviewers.

## DATA ABSTRACTION AND QUALITY ASSESSMENT

All eligible articles underwent independent data abstraction by 2 individuals for: participant characteristics and setting (including country and whether study was conducted in VHA); EBP being evaluated; data sources and analytic methods (eg, semi-structured interviews and framework analysis, or surveys and multivariate logistic regression); and outcomes. We extracted demographic data in categories consistent with terminology used by authors, including gender and sex. For articles evaluating barriers and facilitators, we classified outcomes by domains within the Consolidated Framework for Implementation Research (CFIR).^29,30^ CFIR consists of 5 major domains: I) Intervention characteristics; II) Outer setting; III) Inner setting; IV) Characteristics of the individuals involved; and V) Process of implementation. Each major domain has additional subdomains (see Table 1). CFIR has been recommended as a unifying structure for examining major constructs that influence implementation of evidence-based mental health treatments.^30^ For those that addressed effects of implementation strategies (eg, training and education), we categorized outcomes by RE-AIM: Reach (eg, uptake by target populations); Effectiveness (eg, patient outcomes, cost-effectiveness); Adoption (eg, uptake by providers), Implementation (eg, consistency and fidelity of intervention delivery), and Maintenance (eg, sustainability of effects).^31,32^ We also classified implementation strategies according to the expert recommendations for implementing change (ERIC) project.^33,34^

All quantitative results were abstracted by 1 reviewer and over-read by a second reviewer. Qualitative results were independently coded by at least 2 reviewers, with final codes reached by consensus. A priori codes were generated from either CFIR (for barriers and facilitators) (Table 1 and Appendix C) or RE-AIM (for evaluation of implementation strategies) (Table 2). We allowed for emergence of new codes, if results did not fit well within existing frameworks. We used a best-fit framework synthesis approach to categorize results and adapt the frameworks as needed; we developed new CFIR subdomains within Outer Setting to facilitate interpretation of data on barriers and facilitators. For evaluations of implementation strategies, we categorized provider attitudes and self-efficacy within Adoption, as the most appropriate domain. These provider factors were assessed to improve understanding about why some providers will (or will not) use certain EBPs.

Two reviewers independently assessed quality using criteria adapted from either the Newcastle-Ottawa Scale^35^ (for quantitative studies) and the Critical Skills Appraisal Programme (CASP) Checklist for qualitative studies.^36^ We also rated overall quality as high, moderate, or low. Consensus on quality ratings was reached through discussion. For studies that used mixed-methods (ie, quantitative and qualitative methods), we used both sets of criteria to separately rate the applicable results. Quality assessment criteria can be found in Appendix D.

## DATA SYNTHESIS

Given heterogeneity in populations, different types of EBPs, and variable study designs among eligible articles, we did not conduct quantitative meta-analyses. We undertook a qualitative synthesis, focusing first on results for CBT, ACT, and MBSR for chronic pain. We then summarized results related to use of CBT, ACT, and MBSR to treat other conditions. Finally, we described results regarding other EBPs, including trauma-focused therapies for PTSD (PE and/or CPT), cognitive behavioral social skills therapy (CBSST), MET, contingency management, and Dialectical Behavioral Therapy (DBT).

For all eligible articles (whether using quantitative and/or qualitative methods), we first created tables with detailed results (classified or coded as described above). We then reviewed these results within categories, and across articles addressing the same EBP, to derive themes related to barriers and facilitators for implementation and implementation outcomes. We used CFIR for the synthesis of barriers and facilitators to implementation, and the RE-AIM framework for synthesis of implementation outcomes (with grouping of studies by ERIC strategies).

## RATING THE BODY OF EVIDENCE

A formal certainty of evidence rating was not conducted as part of this review.

## PEER REVIEW

A draft version of this report was reviewed by content experts and VA operational partners. Their comments and our responses are presented in Appendix E and the report has been modified as needed.

Table 1 Adaptation of the Consolidated Framework for Implementation Research (CFIR): Domains and Subdomains^a^

I. Intervention characteristics; A. Intervention source; B. Evidence strength & quality; C. Relative advantage; D. Adaptability; E. Trialability; F. Complexity; G. Design quality & packaging; H. Cost; I. Group dynamics; J. Patient-therapist dynamics; II. Outer setting; A. Patient needs & resources; B. Cosmopolitanism; C. Peer pressure; D. External policies & incentives; E. Patient knowledge & beliefs; F. Other patient attributes; G. General practice climate & patterns; III. Inner setting; A. Structural characteristics; B. Networks & communications; C. Culture; D. Implementation climate; 1. Tension for change; 2. Compatibility; 3. Relative priority; 4. Organizational incentives & rewards; 5. Goals and feedback; 6. Learning climate; E. Readiness for implementation; 1. Leadership engagement; 2. Available resources; 3. Access to knowledge and information; F. Provider decision-making; G. Patient-provider relationships (outside of psychotherapy); IV. Characteristics of individuals; A. Knowledge & beliefs about the intervention; B. Self-efficacy; C. Individual stage of change; D. Individual identification with organization; E. Other personal attributes; V. Process; A. Planning; B. Engaging; 1. Opinion leaders; 2. Formally appointed internal implementation leaders; 3. Champions; 4. External change agents; C. Executing; D. Reflecting & evaluating

a Adapted from Damschroder et al., 2009^29^ and Damschroder and Hagedorn, 2011;^30^ new subdomains noted in italics; see Appendix C for detailed definitions

Table 2 RE-AIM Framework Domains and Definitions^a^

Reach | The absolute number, proportion, and representativeness of individuals who are willing to participate in a given initiative, intervention, or program, and reasons why or why not.; How do I reach the targeted population with the intervention?
Effectiveness | The impact of an intervention on important individual outcomes, including potential negative effects, and broader impact including quality of life and economic outcomes; and variability across subgroups (generalizability or heterogeneity of effects).; How do I know my intervention is effective?
Adoption | (Setting levels) The absolute number, proportion, and representativeness of settings and intervention agents (people who deliver the program) who are willing to initiate a program, and why.; How do I develop organizational support to deliver my intervention?
Implementation | At the setting level, implementation refers to the intervention agents’ fidelity to the various elements of an intervention’s key functions or components, including consistency of delivery as intended and the time and cost of the intervention. Importantly, it also includes adaptations made to interventions and implementation strategies.; How do I ensure the intervention is delivered properly?
Maintenance | At the setting level, the extent to which a program or policy becomes institutionalized or part of the routine organizational practices and policies. At the individual level, maintenance has been defined as the long-term effects of a program on outcomes after a program is completed.; How do I incorporate the intervention so that it is delivered over the long term?

a Definitions from www.re-aim.org and Glasgow et al, 2019^32^, slightly edited for length.