# INTRODUCTION

Chronic pain conditions comprise 3 of the top 5 causes of disability in the United States (US) and contribute to other disabling conditions, such as opioid use disorder (ranked 8^th^).^1^ In 2011-2012, chronic pain was estimated to affect at least 100 million US adults and to cost more than $600 billion in treatment and lost productivity.^2,3^ Research suggests that chronic pain prevalence has continued to increase, with concomitant higher levels of psychological distress.^4^ The persistence or recurrence of pain profoundly impacts physical, mental, and social functioning. Individuals with chronic pain have higher prevalence of mental health conditions, including posttraumatic stress disorder (PTSD), depression, and insomnia; they are also at greater risk for other chronic health conditions.^5–8^ Veterans have a higher prevalence of chronic pain conditions compared to civilians,^8–11^ resulting in significant healthcare costs for the Veterans Health Administration (VHA).^12–14^

People with chronic pain often receive medical treatments, such as opioids and surgery, that have limited benefit in many circumstances and carry higher risk for adverse events.^2,15,16^ The VA/Department of Defense (DoD) clinical practice guidelines and the Centers for Disease Control and Prevention (CDC) guidelines recommend nondrug, noninvasive therapies with demonstrated functional benefits as first- and second-line treatments for chronic pain.^16–19^ First-line options for pain management include evidence-based psychotherapies (EBPs), exercise and physical therapy, and non-opioid medications. EBPs that have demonstrated efficacy for improving chronic pain outcomes include cognitive behavioral therapy (CBT), acceptance and commitment therapy (ACT), and mindfulness-based stress reduction (MBSR).^20,21^ Because research suggests that no single therapy is effective for the majority of patients with chronic pain and pain treatment responses are heterogeneous, experts recommend personalized multimodal care—using multiple treatment approaches in a stepped or integrated fashion.^22^

VA is committed to improving nonpharmacological treatment and reducing opioid-related harms for Veterans with chronic pain.^16,17,19^ VHA has engaged in national dissemination and implementation of EBPs, including CBT for chronic pain,^23,24^ but critical gaps remain. EBPs are underutilized in VHA clinical settings and are not widely integrated into chronic pain care.^25,26^ To help identify areas of research critical for improving uptake of these therapies, the VA Health Services Research & Development (HSR&D) Pain/Opioid Consortium of Research (CORE) requested an evidence review on barriers, facilitators, and implementation strategies for EBPs in chronic pain. We included CBT, ACT, and MBSR since these EBPs have demonstrated efficacy for improving chronic pain outcomes, are included in treatment guidelines for chronic pain, and are being delivered in VHA settings; therefore, implementation research is a logical next step. Additionally, because some findings from implementation of EBPs to treat chronic mental health conditions may be applicable to implementation of EBPs for chronic pain, the Pain/Opioid CORE asked the VA Evidence Synthesis Program (ESP) to identify and summarize studies examining barriers, facilitators, and implementation strategies for these other EBPs. This may be especially true for studies conducted within VHA, where provider- and system-level barriers and facilitators or implementation strategies for other EBPs may more readily generalize to EBPs for chronic pain. Similar to the selection process of EBPs for chronic pain, we included EBPs that have a strong evidence base and are included in treatment guidelines for mental health conditions. Selected EBPs are being delivered at VHA facilities to treat common conditions, including insomnia, depression, and PTSD.

In this systematic review, we sought evidence relevant to implementation of EBPs for chronic pain and chronic mental health conditions, focusing on 1) barriers and facilitators at the patient, provider, and system levels; and 2) results of various implementation strategies aimed at promoting uptake of and engagement with EBPs. We present qualitative summaries of results for barriers and facilitators, focusing first on CBT, ACT, and MBSR for chronic pain and then discussing CBT for other conditions, including insomnia and substance use disorders. Next, we summarize outcomes from use of implementation strategies for increasing uptake of these EBPs, for chronic pain and other conditions. Finally, we summarize results regarding barriers, facilitators, and effects of implementation strategies for additional EBPs for chronic mental health conditions, including trauma-focused psychotherapies for PTSD.