# ABBREVIATIONS TABLE

ACT: Acceptance and commitment therapy
AHRQ: Agency for Healthcare Research and Quality
aOR: Adjusted odds ratio
BDI: Beck Depression Inventory
BPI: Brief pain inventory
CASP: Critical Appraisal Skills Programme
CBT: Cognitive behavioral therapy
t-CBT: Telephone cognitive behavioral therapy
CBT-CP: Cognitive behavioral therapy for chronic pain
CBT-I: Cognitive behavioral therapy for insomnia
CBSST: Cognitive behavioral social skills training
CDC: Centers for Disease Control and Prevention
CFIR: Consolidated Framework for Implementation Research
CESD: Center of Epidemiological Studies Depression Scale
CI: Confidence interval
CM: Contingency management
CORE: VA Pain/Opioid Consortium of Research
CPT: Cognitive processing therapy
DBT: Dialectical behavior therapy
DoD: Department of Defense
EBP: Evidence based psychotherapy
EPC: Evidence-based Practice Center
ERIC: Expert Recommendation for Implementation Change
ESP: Evidence Synthesis Program
GP: General practitioner
HSR&D: VA Health Services Research and Development
IAPT: Improving Access to Psychological Therapies
KQ: Key Question
MET: Motivational enhancement therapy
MSBR: Mindfulness-based stress reduction
NHS: UK National Health Service
NR: Not reported
OCD: Obsessive-compulsive disorder
OR: Odds ratio
PE: Prolonged exposure therapy
PCL: PTSD Checklist
PCMHI: Primary Care Mental Health Integration
PCP: Primary care provider
PSOCQ: Pain Stages of Change Questionnaire
PTSD: Posttraumatic stress disorder
QALY: Quality-adjusted life years
QOL: Quality of life
RCT: Randomized controlled trial
RE-AIM: Reach, effectiveness, adoption, implementation, maintenance
RMDS: Roland-Morris Disability Scale
SD: Standard deviation
SUD: Substance use disorder
TEP: Technical Expert Panel
UC: Usual care
UK: United Kingdom
US: United States
VHA: Veterans Health Administration
WHYMPI-INT: West Haven–Yale Multidimensional Pain Inventory