# APPENDIX G EVIDENCE TABLES

Appendix Table G1 KQ1 Articles Examining Facilitators and Barriers to Implementation of CBT, ACT, and MBSR for Chronic Pain

Appendix Table G2 KQ2 Articles Examining Facilitators and Barriers to Implementation for CBT and CBSST for Chronic Mental Health Conditions

Appendix Table G3 KQ2 Articles Evaluating Implementation Strategies for CBT, ACT, DBT, MET, and Contingency Management

Appendix Table G4 KQ2 Articles Evaluating Implementation Strategies for Trauma-focused Psychotherapies for PTSD (CPT and PE)

Appendix Table G5 KQ2 Articles Evaluating Barriers and Facilitators to Implementation of Trauma-focused Psychotherapies for PTSD (CPT and PE)