# APPENDIX F QUALITY ASSESSMENT FOR ELIGIBLE PUBLICATIONS

Appendix Table F1 Quality Ratings for Qualitative Studies Assessed with CASP

Author, Year | Was there a clear statement of the aims of the research? | Is qualitative methodology appropriate? | Was the research design appropriate to address the aims of the research? | Was the recruitment strategy appropriate to the aims of the research? | Was the data collected in a way that addressed the research issue? | Has the relationship between researcher and participants been adequately considered? | Have ethical issues been taken into consideration? | Was the data analysis sufficiently rigorous? | Is there a clear statement of findings? | Overall study quality
Amodeo 2011^97^ | Yes | Yes | Yes | Can’t Tell | Can’t Tell | No | Yes | Can’t Tell | Yes | Low
Bee 2016^45^ | Yes | Yes | Yes | Yes | Yes | No | Yes | Yes | Yes | Moderate
Brintz 2020^38^ | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Yes | High
Casey 2020^54^ | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Yes | High
Clarke 2017^42^ | Yes | Yes | Yes | Yes | Yes | No | Yes | Yes | Yes | Moderate
Crisp 2016^44^ | Yes | Yes | No | No | Can’t Tell | No | Yes | No | Can’t Tell | Low
Curran 2015^81^ | Yes | Yes | Yes | Yes | Yes | Yes | Yes | No | Yes | High
Doran 2019^61^ | Yes | Yes | No | No | Yes | Yes | Yes | Yes | Yes | Low
Fraser 2019^40^ | Yes | Yes | Yes | Yes | Yes | No | Yes | Yes | Yes | High
George 2017^43^ | Yes | Yes | Yes | No | Can’t Tell | Yes | Yes | Yes | Yes | Moderate
Hamblen 2015^102^ | Yes | Yes | Yes | Yes | Yes | No | Yes | Yes | Yes | High
Hundt 2015^70^ | Yes | Yes | Yes | Yes | Yes | No | Yes | Yes | Yes | High
Hundt 2018^62^ | Yes | Yes | Can’t Tell | Yes | Yes | No | Yes | Can’t Tell | Yes | Moderate
Kauth 2010^89^ | Yes | Yes | Yes | Yes | Yes | No | Yes | Can’t Tell | Yes | Moderate
Koffel 2020^59^ | Yes | Yes | Yes | Yes | Yes | No | Yes | Yes | Yes | High
Koffel 2020^57^ | Yes | Yes | Yes | Yes | Yes | No | Yes | Yes | Yes | High
Kyrios 2010^98^ | Yes | Yes | Can’t Tell | Yes | Can’t Tell | No | Yes | Can’t Tell | Yes | Low
Landes 2017^95^ | Can’t Tell | Yes | Can’t Tell | Can’t Tell | Can’t Tell | No | Yes | Can’t Tell | Yes | Low
Lu 2016^68^ | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Yes | Yes | High
Martinez 2015^56^ | Yes | Yes | Yes | Yes | Yes | No | Yes | Can’t Tell | Yes | Moderate
McCracken 2014^47^ | Yes | Yes | Yes | Yes | Yes | No | Yes | Can’t Tell | Yes | Moderate
Osei-Bonsu 2017^67^ | Yes | Yes | Yes | Yes | Yes | No | Yes | Yes | Yes | High
Patel 2009^49^ | Yes | Yes | Can’t Tell | Can’t Tell | Yes | No | Yes | Can’t Tell | Yes | Moderate
Possemato 2018^75^ | Yes | Yes | Yes | Yes | Yes | No | Yes | Yes | Yes | High
Sayer 2017^65^ | Yes | Yes | Yes | No | Yes | No | Yes | Yes | Yes | Moderate
Sommerfeld 2019^99^ | Yes | Yes | Yes | Yes | Yes | No | Yes | Yes | Can’t Tell | Moderate
Van Huet 2009^48^ | Yes | Yes | Yes | Yes | Yes | No | Yes | Yes | Yes | Moderate

Appendix Table F2 Quality Ratings for Quantitative Studies Assessed with Newcastle-Ottawa

Author, Year | Representative of the population, with clear sampling strategy and rationale? | Ascertainment of condition | Implementation strategy and rationale clearly described? | Appropriate outcome assessment (datasources, variable definitions and rationale clearly described)? | Complete follow-up and/or adequate response rate (>60%)? | For implementation trials testing a specific strategy, was the follow-up sufficient for outcomes? | Was the data analysis sufficiently rigorous? | Has the relationship between researcher and participants been adequately considered? | Have ethical issues been taken into consideration? | Overall quality rating
Brintz 2020^38^ | No | Medical record or clinical diagnosis | NA | Yes | Yes | NA | Unclear | Yes | Yes | Moderate
Chard 2012^87^ | Yes | NA | Yes | Yes | No | Yes | No | No | No | Low
Charney2019^74^ | No | NA | Yes | Yes | Unclear | Yes | Yes | No | Yes | Low
Clark 2009^94^ | Unclear | Unclear | No | No | Unclear | No | No | No | Yes | Low
Crawford 2017^77^ | No | Medical record or clinical diagnosis | NA | Yes | Yes | NA | Yes | No | Yes | Moderate
Crisp 2016^44^ | No | Medical record or clinical diagnosis | NA | Yes | No | NA | No | No | Yes | Low
Cully 2010^88^ | Yes | NA | Yes | Yes | Yes | Yes | No | No | Yes | Moderate
Dedert 2020^73^ | No | Medical record or clinical diagnosis | Yes | No | Unclear | NA | No | No | Yes | Low
DePhilippis 2018^100^ | Unclear | NA | No | No | Unclear | Yes | No | No | Yes | Low
Doran 2019^61^ | No | work at PTSD clinic | No | Yes | Unclear | NA | Yes | Yes | | Moderate
Drapkin 2016^79^ | Yes | NA | Yes | Yes | Yes | Yes | Yes | No | Yes | High
Eftekhari 2015^82^ | No | Medical record or clinical diagnosis | NA | Yes | Unclear | NA | Yes | No | Yes | Moderate
Finley 2015^71^ | Yes | NA | NA | No | No | NA | Yes | No | Yes | Moderate
Finley 2018^63^ | Yes | NA | NA | Yes | No | NA | Yes | No | Yes | Moderate
Garcia 2019^60^ | Yes | NA | NA | Yes | No | NA | Yes | No | Yes | Moderate
Garcia 2020^101^ | Yes | NA | NA | Yes | No | NA | Yes | No | Yes | Moderate
George 2017^43^ | No | Unclear | NA | Yes | Yes | NA | Yes | No | Yes | Moderate
Heapy 2005^50^ | Yes | Medical record or clinical diagnosis | NA | Yes | Yes | NA | Yes | No | Yes | High
Hepner 2011^90^ | Yes | Medical record or clinical diagnosis | Yes | Yes | Yes | No | Yes | No | Yes | Moderate
Herman 2017^55^ | Yes | Medical record or clinical diagnosis | NA | Yes | Yes | NA | Yes | No | Yes | High
Higgins 2018^41^ | Yes | Medical record or clinical diagnosis | NA | Yes | Yes | NA | Yes | No | Yes | High
Hundt 2018^62^ | No | Unclear | No | Yes | No | NA | Yes | | | Low
Karlin 2010^91^ | Yes | NA | Yes | No | Unclear | No | Unclear | No | Yes | Low
Karlin 2012^93^ | Yes | NA | Yes | Yes | Yes | Yes | Yes | No | Yes | Moderate
Karlin 2013^85^ | Yes | NA | Yes | Yes | Yes | No | Yes | No | Yes | Moderate
Kauth 2010^89^ | Yes | NA | Yes | Yes | Yes | Yes | Yes | No | Yes | High
Kauth 2017^96^ | Unclear | NA | Yes | No | Yes | Yes | Yes | Yes | No | Moderate
Kerns 2000^51^ | Yes | Medical record or clinical diagnosis | NA | Yes | Unclear | NA | Yes | No | Yes | Moderate
Koffel 2018^52^ | Yes | Medical record or clinical diagnosis | NA | Yes | Yes | NA | Yes | No | Yes | High
Kyrios 2010^98^ | Unclear | NA | NA | No | Unclear | NA | No | No | Yes | Low
Manber 2013^92^ | Yes | NA | Yes | Yes | Yes | No | No | Yes | No | Moderate
McCracken 2014^47^ | Yes | Medical record or clinical diagnosis | NA | Yes | Yes | NA | Unclear | No | Yes | Moderate
Mignogna 2014^86^ | No | Medical record or clinical diagnosis | Yes | Yes | Yes | Yes | Yes | No | Yes | Moderate
Mun 2019^39^ | Yes | Medical record or clinical diagnosis | NA | Yes | Yes | NA | Yes | No | Yes | High
Murphy 2020^37^ | No | Medical record or clinical diagnosis | NA | Yes | No | NA | Unclear | | Yes | Moderate
Possemato 2018^75^ | Yes | PCL-S score | Yes | Yes | Yes | Yes | Yes | No | Yes | High
Raza 2015^69^ | Yes | NA | NA | Yes | No | NA | No | No | Yes | Moderate
Richards 2017^66^ | No | NA | Yes | No | No | NA | Yes | No | No | Low
Rosen 2017^76^ | Yes | NA | Yes | Yes | Yes | Yes | Yes | No | Yes | High
Ruzek 2014a^83^ | Yes | NA | Yes | Yes | No | Yes | Yes | No | Yes | Moderate
Ruzek 2014b^72^ | No | NA | NA | Yes | Yes | NA | No | No | No | Low
Ruzek 2016^80^ | Yes | NA | Yes | Yes | Yes | Yes | Yes | No | Yes | High
Ruzek 2017^78^ | Yes | NA | Yes | Yes | Yes | Yes | Yes | No | Yes | High
Song 2020^58^ | Yes | NA | NA | No | No | NA | Yes | No | Yes | Moderate
Stewart 2015^24^ | Yes | Medical record or clinical diagnosis | Yes | Yes | Yes | Yes | Unclear | No | No | Moderate
Thorn 2011^53^ | Yes | Medical record or clinical diagnosis | NA | Yes | Yes | NA | Yes | No | Yes | High
Ulmer 2017^64^ | Yes | NA | NA | Yes | No | NA | Yes | No | Yes | Moderate
Walser 2013^84^ | Yes | NA | Yes | Yes | Yes | No | Yes | No | Yes | High
Wetherell 2016^46^ | Yes | Study staff evaluation of participants | NA | Yes | Yes | NA | Yes | No | Yes | High