# APPENDIX E PEER REVIEW DISPOSITION

| Reviewer Comments | Authors’ Responses
Reviewer 2:
2.1 | “I have generally only praise for this excellent report. I have no significant substantive concerns, and my comments are primarily editorial in nature.; I note that the Executive Summary is over 30 pages, and the full report is about three times as long. If feasible, i think that it could be useful to try to shorten the Executive Summary to better isolate and highlight key findings. In particular, it seems possible to more succinctly present some of the details of the methods in the Executive Summary.” | Thank you.; We have edited the Methods in the Executive Summary to be more succinct. Currently, the Methods are less than 2 pages and we note that we are reporting methods information that is strongly recommended for systematic reviews (eg, by PRISMA). We agree that the Executive Summary is on the longer side, but this is largely due to the amount of results that cover quite a broad scope across the 2 KQ.
2.2 | “I think that it would be helpful to add some background information, presumably from the HSR&D SOTA on nonpharmacological approaches to management of chronic musculoskeletal pain, that provides a justification and rationale for focusing solely on CBT, ACT and mindfulness approaches when examining the literature on evidence based approaches for management of chronic pain. That is, why were hypnosis, biofeedback, meditation and other self-regulatory approaches not considered, given that they each have evidence of efficacy for at least some subgroups of patients with chronic pain and since they are all in use in at least some VHA facilities?” | We included CBT-CP, ACT, and MBSR since these EBPs have demonstrated efficacy for improving chronic pain outcomes (as noted by the HSR&D SOTA on non-pharmacological approaches to management of chronic musculoskeletal pain), are included in treatment guidelines for chronic pain and are being delivered in VHA settings, making implementation research a logical next step. We understood these priorities to be those of the requesting Operational Partners as well. We have commented on the rationale further in the Introduction and Methods.; Several self-management strategies, and provider-delivered strategies not involving conscious psychotherapy with participants, have some evidence supporting their use as treatments for chronic pain. As these vary broadly with respect to roles of patients and providers, necessary technologies, and other clinical resources, it is likely that relevant barriers, facilitators, and implementation work would be distinct from those relevant to EBPs as well. Accordingly, these approaches to chronic pain care were considered beyond the scope of this review. Should these treatments be high priority for VA stakeholders, we would encourage that future systematic reviews to evaluate evidence for implementation of these self-management strategies and provider-delivered strategies beyond participatory psychotherapy.
2.3 | “Similarly, the expanded group of psychotherapies that were considered in addressing KQ2 might be justified. And, in interpreting the findings from this search, i think that it could be important to expand a bit on fairly obvious differences in some of these approaches (e.g., CPT and PE for PTSD) and those employed for chronic pain management. In this context, it seems likely that it could be important to acknowledge that, although depressive and anxiety disorders and PTSD commonly co-occur with chronic pain, they are distinct disorders with clinical characteristics that could be serve to elicit distinctly different barriers and facilitators for implementation and widespread adoption… “ | We have edited the Discussion to expand on the differences of the KQ2 psychotherapy approaches relative to those employed for chronic pain management and have clarified that there may be different barriers and facilitators for therapies for non-pain conditions.
2.4 | “Consistently use CBT or CBT-CP; probably the former, since ACT and MBSR are not hyphenated when denoting that the intervention was for chronic pain.; Page 3, Line 60 – “Over half” not “galf.”; Be consistent in referencing “gender” and use "sex” only when referring to sex as a biological variable.; Be consistent using “VHA” rather than “VA.”; Page 23 – Spell out acronyms (e.g., CBSST, MET).”.” | We agree that this distinction is important and that our search identified uses of CBT for chronic pain that might not formally be considered CBTCP. In some articles, including those evaluating the national VHA rollout of CBT for chronic pain, CBT approaches were specifically described as a standardized form of CBT for chronic pain and abbreviated as CBT-CP (Stewart et al 2015, Murphy et al 2020, Higgins et al 2018). We have kept the term CBT-CP when referring to findings from those articles, and have removed the “CP” suffix from other mentions of CBT.; This has been corrected.; We agree it is important to use accurate descriptions of gender and sex. None of the included articles defined gender, sex, race or ethnicity, and most used secondary analyses of administrative or medical chart data. Accordingly, we could not independently determine whether gender or sex was assessed in the articles. We used gender or sex terminology consistent with the terms authors used to describe their results. We have edited Methods and Results to clarify this process and ensure consistency throughout the text. We have now noted in Results the finding that no included articles clearly defined sex, gender, race or ethnicity and that we could not verify the accuracy of these terms as applied to the data analyzed. We agree that there is significant concern regarding the use of how gender and sex are assessed and considered in analyses, and in the Discussion, we raised this issue with the published literature. We have added to our suggestions for future research the need to analyze these proxies, along with race and ethnicity, accurately and with clear purpose.; We have confirmed consistent use of “VHA” throughout the report. By convention, we refer to non-VA community settings, as these are entirely outside of VA programs (not just VHA facilities and clinics). We have also used “VA” or “VHA” if this was part of participant quotes as reported by included studies.; Per ESP Coordinating Center guidance, acronyms should be spelled out at first use and then abbreviated thereafter. We confirmed that all acronyms are spelled out at first use and included in the Abbreviations Table found at the end of the Executive Summary.
Reviewer 5:
5.1 | “Page 11, Line 34 – Under “Key Results,” it is noted first here (but several times in manuscript), that they included “cultural and communication barriers.” I have searched the results and there appears to be only a single qualitative look at GPs impressions re: CBT on which this finding is based. The GPs (in the UK I believe) mention that a specific group (South Asians in this case) could perhaps be better served with more culturally sensitive materials/this approach may not work well for that culture. Since this is reported as a Key Finding, I thought this would at least be present in 2 studies and/or would be from a patient standpoint vs a GP opinion (who admittedly in the same study also said they did not fully understand CBT options) and/or would be more generalizable. While I am not arguing against this as a basic point in probably all treatment, since there is really not evidence to support it I am concerned about it being listed here as a key barrier to CBT.; It seems important when it comes to key findings that it comes up in more than 1 study and has more generalizable implications. Or if it is from a single qualitative study to note it as you have below.” | We agree that Patel et al 2009 is the only study we found in which primary care providers noted cultural barriers to CBT use for chronic pain specifically. It is also the only study we found focused on primary care providers’ perspectives regarding barriers to CBT use for chronic pain – and in that sense, 100% of such studies identified cultural barriers to CBT use for chronic pain. As we noted in the report, an additional study of CBT providers’ perspectives on CBT use for other mental health conditions noted cultural and language barriers as a theme (Amodeo et al 2011). No studies explored roles of culture, race, sex, gender, or social factors in patients’ own views or experiences of EBPs, and it is difficult to infer that this absence of evidence is evidence of absence.; We do not use a quantitative criterion for determining key results. Even in reviews focused on data from randomized controlled trials, 1 large, highquality study may be definitive in determining the key results. As much of the evidence in this review comes from qualitative studies, we find that quantifying the frequencyof studies (as an indicator of the importance of reported results) to be potentially even more problematic. There were few studies that examined certain areas (eg, provider and system level factors for KQ 1), and studies varied greatly in comprehensiveness of evaluations. Thus, we used iterative rounds of discussion and consensus-building to arrive at our synthesis of results, with the goal of emphasizing those findings that are most likely to be important and/or point to key questions needing further research. We agree that current evidence are insufficient to indicate specific areas of need for cultural or social adaptations to EBPs. As the reviewer notes, additional research is needed to clarify roles of cultural and communication barriers in EBP uptake. We have edited the Executive Summary and Discussion to reflect this.
5.2 | “Page 35, Line 22 (Page 37, Line 4) – The heterogeneity in treatment response is mentioned several times in the manuscript; however, I could not find these differences summarized succinctly.; The results re: demographics, etc. seemed highly variable re: possible impacts on treatment effects. Is it possible to explain in a more direct way about the heterogeneity in treatment response? Do these not work for most or for only certain groups, types of pain, etc.?.” | Heterogeneity in both treatment effects and treatment uptake is evident in research on EBPs, for chronic pain and for other behavioral health conditions, yet research on patient-level factors affecting both types of heterogeneity is limited to date. We found a wide range of patient-level factors related to uptake of EBPs for chronic pain, as noted in the report; some of these, such as patient beliefs about therapies or about pain, have especially plausible relationships to treatment effects as well. Our findings with respect to patient-level demographic factors related to treatment uptake were highly variable, as this reviewer notes and as we noted in the report. Further, as noted in the report and in comments above, conceptual and data-related definitions of many demographic variables were not well reported. More consistent and substantive assessment of heterogeneity in both treatment effects and treatment uptake, in both observational work and RCTs, can help clarify more patient-level targets for both effectiveness and implementation work – and can ensure clarity as to which factors affect treatment effectiveness, implementation, or both. We have edited the Executive Summary and Discussion to clarify these points.
5.3 | “Page 37, Line 56-57 – Since there was no information re: group implementation of CBT-CP and limited info on individual delivery of the other modalities, it seems that a future research interest may be gathering more of this data. | We agree it is an important finding that no studies analyzed barriers, facilitators, or implementation strategies for group CBT for chronic pain, individual ACT for chronic pain, or individual MBSR for chronic pain. While MBSR was developed in a group format for chronic pain as well as for other mental health conditions, both CBT and ACT are provided regularly in both group and individual formats. We have edited the Implications section to draw more attention to the importance of group vs individual therapy formats in evaluation, and have edited the Research Gaps/Future Research section to indicate the need for future research on formatspecific effectiveness and implementation work for both CBT and ACT for chronic pain.
5.4 | “Page 38, Line 11 – States to “Describe reach for EBPs associated with implementation strategies, such as VHA national training programs for EBPs” – What does this mean exactly and where would like to see it described? In general, the EBP Program has a transparent training structure, make available its information re: number of providers trained, etc. The tracking of encounters using many EBPs has been a challenge within VHA for a variety of reasons including IT barriers, etc. This may be more of an internal ask versus a future research question?” | In our Discussion, we summarized findings regarding Adoption ([underlined: eg], number of providers using EBPs) but also highlighted the need to evaluate Reach, defined as the number and representativeness of patients who are using the recommended treatments. As noted by the reviewer, there are challenges to assessing Reach, and we have added this consideration to the Discussion. However, we believe that Reach remains critical for evaluation of implementation strategies (within VHA and in the community). Additionally, we have expanded the RE-AIM definitions in the Methods to better distinguish between Adoption and Reach.
Reviewer 6:
6.1 | “Minor comments; p. 9, lines 8 through 17 – I recommend bold/italics for the key differences between KQ1 and KQ2 (e.g., chronic pain vs chronic mental health conditions).; p. 10, line 60 – galf = half; p. 11, lines 30/31 – should be “except” (instead of excepting); p. 21, lines 51/52 – need to remove ‘d’ from “received”; p. 42, lines 7/8 to 9 – Phrasing is a little unusual, maybe change to, “Across 2011 and 2012, chronic pain was estimated…”; p. 45, lines 17/18 – there is an underline before Consolidated that needs to be removed.” | We have bolded the words “chronic pain” (KQ 1) and “chronic mental health conditions” (KQ 2). We have also made the remaining corrections.
6.2 | Content-related comments; p. 9, lines 17/18 – Why are not patient barriers mentioned as part of KQ2a?; p. 10, lines 10/11 – RE-AIM is not specifically for evaluating implementation strategies per se, but implementation more broadly. Do you want to make that distinction?” | In the Introduction, we have expanded on the rationale of including evidence on implementation of psychotherapies for non-pain conditions. Because the main goal of our stakeholders was to improve implementation of therapies for chronic pain, we considered that there would be more concerns with applicability of evidence for patient-level barriers and facilitators when these were non-pain populations. Therefore, KQ 2 focuses on provider and system-level barriers and facilitators. We have also added this clarification to the Methods (Topic Development in the main text).; RE-AIM is 1 of several frameworks commonly used to guide evaluations of implementation of clinical and public health interventions (eg, see Hagedorn et al. Addict Sci Clin Pract 2014;9:12). Among the ones we examined, we also felt that it was the most helpful for organizing results from implementation evaluation studies.
6.3 | “p. 21, lines 7-9 – I realize you are looking at the effect of implementation strategies, but I think it would be good to provide a summary of the implementation strategies used in this section, before describing effects of implementation strategies. This also applies to p. 68 where this section starts in the body of the report.” | We have included a new subheading “Implementation Strategies Evaluated” to provide a summary of implementation strategies in both the Executive Summary and Results.
6.4 | p. 21, line 17 – you describe “uptake by target patient population.” We usually refer to that as reach and not uptake in the implementation realm. Might be good to use reach, particularly since you’re using RE-AIM.” | We now use the term reach to describe uptake by target patient population and adoption to describe adoption by clinical staff in the Executive Summary and Results Section.
6.5 | p. 22, lines 47/48 – I see you leave out “Reach.” Was it really left out of the outcomes? If so, I would be more definitive about that in the last sentence of lines 44 to 45 and the accompanying section in the report. I see on p. 73 that these are the only adoption measures across implementation strategies. | We have clarified in the Executive Summary and Results that no results in this classification group reported on Reach.
6.6 | p. 23, lines 3 to 7/8 - Your definition of adoption includes willingness to adopt, but self-efficacy is not quite that. Maybe this more of a facilitator? Positive attitudes has the same issue to me.; This would of course need to be resolved throughout. | For evaluations of implementation strategies, we categorized provider attitudes and self-efficacy within Adoption, as the most appropriate domain. As reported by study authors, these provider factors were assessed to improve understanding about why some providers will (or will not) use certain EBPs. Thus, they directly address the issue of Adoption, per the RE-AIM framework. We have clarified this classification in the Methods, and note it also in the relevant Results section.
6.7 | p. 68, line 44 – Would it be possible to start a new paragraph describing the implementation strategies used? I keep wanting that framing when reading about strategies. It is buried a bit and could be its own section describing definitions of implementation strategies. | See response to #6.3 above
6.8 | p. 97, first bullet point - I think that you want to highlight that you recommend "tailored patient educational materials" based on your previous summary. | We have revised this bullet to better align with the language used in the preceding summary paragraphs.
Reviewer 7:
7.1 | Page 3, line 60 should read "…half…" (not "galf"); page 5, line 52 appears to be missing a word "…fit the program into their, but.."; page 12, line 59 appears to be missing a word "…first launched settings." Page 19, line 49 requires a capital letter (One) after a period.; Page 21, line 21 "…use of adherence…" sounds awkward. Page 21, line 45 should read "…availability of PTSD treatments…"; Page 27, line 10 should read "skills" (not "kills");; Page 65, line 43 should read "There were also more…"; Page 88, line 28 should read "…provider skills…"; Page 29, line 29 recommends development/dissemination of patient educational materials - please note that the National EBP Training programs have developed/disseminated Veteran-facing brochures for each EBP offered, as well as a "Proven Treatments" brochure that provides a brief summary of all EBPs offered.; Page 29, line 32 recommends evaluation of in-person vs TMH care. Please note that the National EBP Training Programs have begun evaluation of EBPs provided to Veterans via TMH vs inperson. | We have made all of these corrections and edits.; We appreciate this information and have added these resources to the range of patient-facing educational materials currently available. However, we believe that our recommendation for more tailored materials for different patient groups remains valid.; Thank you for this information. We have added to the Discussion that there are efforts underway.
Reviewer 8:
8.1 | “Overall, I enjoyed reading this thorough treatment of the implementation literature in this area. It was well-written, and I appreciated the synthesis of a large amount of material to arrive at several clear, pertinent recommendations. Below are additional major and minor comments for consideration.; Major comments:; Page 1, line 41-43- "because some findings from implementation of EBPs to treat chronic mental health conditions may be applicable to implementation of EBPs for chronic pain". Consider adding an explanation that this may be especially true for studies conducted within the VA health system where provider and system factors are expected to be similar and may reveal some common factors (barriers, facilitators, or implementation strategies) that could be acted on at a systems level. It seems important to clarify the purpose of going beyond examining just EBPs for pain.; Page 1, line 49- the scope of this report is wide-ranging, so it is necessarily difficult to organize. This paragraph stating the overall scope of the review was a bit confusing. It may be due to the sentence about "results on barriers and facilitators for these same EBPs but in the context of treating individuals with other conditions". The sentence was unexpected and interrupted the flow. A slightly different presentation or organization may be helpful here.; Also, within this paragraph or prior to it, the point could be made that the EBPs chosen are part of the VA’s EBP program and used to treat conditions that are commonly found in VA including; insomnia, depression, and PTSD.” | Thank you.; We have clarified in the Introduction in the Executive Summary and Introduction in the main text that within VHA, provider- and system-level barriers, facilitators or implementation strategies for EBPs for mental health conditions may generalize to chronic pain treatment. We have also reorganized and expanded the inclusion criteria for non-pain EBPs, including a strong evidence-base, inclusion in treatment guidelines, and common implementation and delivery in VHA settings.
8.2 | “CFIR; I don’t claim expertise in CFIR or RE-AIM, but there were a few places in the report where the classification of themes was not clear to me. Someone with experience with these frameworks should review the manuscript and provide their feedback on the use of the frameworks for classifying the themes in this review. For example, is it acceptable to create new CFIR subdomains?; Page 5, paragraph beginning line 5, the authors created new; CFIR subdomains to describe the themes not present in CFIR, but "Patient Knowledge and Beliefs" and "Other Patient Attributes" are already CFIR subdomains.” | We have carefully reviewed publications and other references describing the selected frameworks, and “Patient Knowledge and Beliefs” and “Patient Other Attributes” are not existing CFIR domains (Damschroder et al. 2009 and Damschroder et al. 2011). CFIR has “Patient Needs and Resources” under Outer Settings, but no other subdomains that specifically address patient attributes. Modifying CFIR has also been done by other groups who found that adding patient-centered subdomains served the purpose of their work (Safaeinili et al. Learn health Syst 2019;4:e10201). Finally, some members of the ESP review team have prior experience with implementation research using these frameworks.
8.3 | Page 12, line 29- this new section of CBT interventions for other conditions could benefit from a sentence or two introduction or maybe be integrated into the EBPs for other conditions section. It isn’t clear what the rationale is for presenting them separately. Later, as I continued to read it was clear that this grouping of studies focuses mostly on provider and system barriers and facilitators rather than patient level barriers and facilitators as the pain related EBPs did and that may be the reason for the separate grouping. Possibly if the rationale for the grouping is introduced earlier it may flow more for the reader. | We have added a description of KQ 2a, which focuses on provider and system-level barriers and facilitators for EBP in chronic mental health conditions.
8.4 | Page 15-16-Adoption-Is this adoption? I have typically seen adoption defined by the number of clinicians or patients who use an intervention. Having said that, I’m not sure where else in the RE-AIM framework I would put this. | As noted previously in response to reviewer #6, we categorized provider attitudes and self-efficacy within Adoption, as the most appropriate domain within RE-AIM. We agree with reviewer that provider attitudes and selfefficacy is not explicitly included in the definition of RE-AIM domains. However, as these are factors that contribute to why (and which) providers will use recommended EBPs, we believe these concepts fit best within Adoption.
8.5 | Page 30, line 27 about reach in VA programs. Great point and I would add that we don’t understand who engages in treatments and which setting have the highest referral yield (the most patients who actually engage). | We agree with the reviewer, and in particular for chronic pain psychotherapies, understanding Reach will also require more research into provider and system-level factors that impact referrals and treatment engagement. We have added these comments to the Discussion (Research Gaps/Future Research).
8.6 | “Minor comments:; Page 1, line 36- consider ‘reducing opioid related harms rather than reducing inappropriate opioid prescribing; Page 3, line 60- should be over half rather than half;; Page 6, line 29-consider adding to the end of that sentence that acceptance is a core process of ACT; Page 8, line 34-consider saying treatment attendance or engagement instead of adherence; Page 19. Line 49. One should be capitalized and have a space I front of it; Page 25, line 52 To support the VA HSR&D Pain/Opioid CORE’s goal of identifying high priority research within implementation of nonpharmacological treatments.”; Page 12, line 42- I wasn’t sure what cognitive barriers meant here. Does this refer to cognitive deficits like dementia or is this something else? | We added language on the goals of the Pain/Opioid CORE to the; Introduction. We have made the remaining suggested edits in the report.; The authors did not elaborate beyond “cognitive barriers to understanding CBT concepts” and therefore it is unclear if this refers to clinical conditions or difficulty understanding CBT concepts.