# APPENDIX D ADAPTED QUALITY ASSESSMENT CRITERIA

## OTTAWA-NEWCASTLE (MODIFIED)

### Selection

1) [underlined: Representativeness of sample]
  a) Yes—representative of the population, with clear sampling strategy and rationale
  b) No—convenience sample, etc.
  c) Unclear—sample not described
2) [underlined: Ascertainment of condition]
  a) Medical record or clinical diagnosis
  b) Other
  c) Unclear—not described
  d) Not Applicable

### Intervention

1) [underlined: Implementation strategy and rationale]
  a) Yes—strategy and rationale clearly described
  b) No—strategy not clear and/or no rationale provided
  c) not applicable

### Outcome

1) [underlined: Appropriate outcome assessment]
  a) Yes—Data sources, variable definitions and rationale clearly described.
  b) No—measures/metrics not well described or use of inappropriate data sources
2) [underlined: Follow-up and response rates]
  a) Complete follow-up and/or adequate response rate (≥60%)
  b) High # lost to follow-up or inadequate response rate
  c) Unclear
3) [underlined: For implementation trials (ie, testing specific strategy), was the follow-up sufficient for implementation outcomes (eg, sustainability, maintenance of effects)]
  a) Yes—sufficient follow-up
  b) Not sufficient
  c) Not Applicable

### Ethics

1) [underlined: Has the relationship between researcher and participants been adequately considered?]
  HINT: Consider
  - If the researcher critically examined their own role, potential bias and influence during (a) formulation of the research questions (b) data collection, including sample recruitment and study setting
  - How the researcher responded to events during the study and whether they considered the implications of any changes in the research design
    a) Yes
    b) Can’t tell
    c) No
2) [underlined: Have ethical issues been taken into consideration?]
  HINT: Consider
  - If there are sufficient details of how the research was explained to participants for the reader to assess whether ethical standards were maintained
  - If the researcher has discussed any issues raised by the study (e.g. issues around informed consent or confidentiality, or how they handled the effects of the study on the participants during and after the study)
  - If approval has been sought from the ethics committee
    a) Yes
    b) Can’t tell
    c) No

## CRITICAL APPRAISAL SKILLS PROGRAMME (MODIFIED)

1. Was there a clear statement of the aims of the research?
  HINT: Consider
  - what was the goal of the research
  - why it was thought important
  - its relevance
    a) Yes
    b) Can’t tell
    c) No
2. Is a qualitative methodology appropriate?
  HINT: Consider
  - If the research seeks to interpret or illuminate the actions and/or subjective experiences of research participants
  - Is qualitative research the right methodology for addressing the research goal
    a) Yes
    b) Can’t tell
    c) No
3. Was the research design appropriate to address the aims of the research?
  HINT: Consider
  - if the researcher has justified the research design (e.g. have they discussed how they decided which method to use)
    a) Yes
    b) Can’t tell
    c) No
4. Was the recruitment strategy appropriate to the aims of the research?
  HINT: Consider
  - If the researcher has explained how the participants were selected
  - If they explained why the participants they selected were the most appropriate to provide access to the type of knowledge sought by the study
  - If there are any discussions around recruitment (e.g. why some people chose not to take part)
    a) Yes
    b) Can’t tell
    c) No
5. Was the data collected in a way that addressed the research issue?
  HINT: Consider
  - If the setting for the data collection was justified
  - If it is clear how data were collected (e.g. focus group, semi-structured interview etc.)
  - If the researcher has justified the methods chosen
  - If the researcher has made the methods explicit (e.g. for interview method, is there an indication of how interviews are conducted, or did they use a topic guide)
  - If methods were modified during the study. If so, has the researcher explained how and why
  - If the form of data is clear (e.g. tape recordings, video material, notes etc.) • If the researcher has discussed saturation of data
    a) Yes
    b) Can’t tell
    c) No
6. Has the relationship between researcher and participants been adequately considered?
  HINT: Consider
  - If the researcher critically examined their own role, potential bias and influence during (a) formulation of the research questions (b) data collection, including sample recruitment and choice of location
  - How the researcher responded to events during the study and whether they considered the implications of any changes in the research design
7. Have ethical issues been taken into consideration?
  HINT: Consider
  - If there are sufficient details of how the research was explained to participants for the reader to assess whether ethical standards were maintained
  - If the researcher has discussed issues raised by the study (e.g. issues around informed consent or confidentiality or how they have handled the effects of the study on the participants during and after the study)
  - If approval has been sought from the ethics committee
    a) Yes
    b) Can’t tell
    c) No
8. Was the data analysis sufficiently rigorous?
  HINT: Consider
  - If there is an in-depth description of the analysis process
  - If thematic analysis is used. If so, is it clear how the categories/themes were derived from the data
  - Whether the researcher explains how the data presented were selected from the original sample to demonstrate the analysis process
  - If sufficient data are presented to support the findings
  - To what extent contradictory data are taken into account
  - Whether the researcher critically examined their own role, potential bias and influence during analysis and selection of data for presentation
    a) Yes
    b) Can’t tell
    c) No
9. Is there a clear statement of findings?
  HINT: Consider whether
  - If the findings are explicit
  - If there is adequate discussion of the evidence both for and against the researcher’s arguments
  - If the researcher has discussed the credibility of their findings (e.g. triangulation, respondent validation, more than 1 analyst)
  - If the findings are discussed in relation to the original research question
    a) Yes
    b) Can’t tell
    c) No