# APPENDIX B ELIGIBILITY CRITERIA

| INCLUSION CRITERIA
| KQ 1 | KQ2
Populations | Community-dwelling adults with chronic pain (ie, pain ≥ 3 months; described as "chronic pain"; or included pain conditions such as fibromyalgia or arthritis) | Community-dwelling adults with chronic mental health conditions
Interventions | - Cognitive behavioral therapy; - Mindfulness-based stress reduction; - Acceptance & commitment therapy | - Cognitive behavioral therapy; - Mindfulness-based stress reduction; - Acceptance & commitment therapy; - Cognitive processing therapy; - Interpersonal psychotherapy; - Prolonged exposure therapy; - Cognitive behavioral conjoint therapy; - Contingency management; - Couples & family therapy; - Social skills training; - Dialectical behavioral therapy; - Present centered therapy; - Motivational enhancement therapy; - Problem solving therapy
Comparators | Any (active or inactive)
Outcomes | Pre-implementation studies:; - Patient-, provider-, and system-level barriers and facilitators | Pre-implementation studies:; - Provider- and system-level barriers and facilitators
Outcomes | Evaluations of implementation strategies:; - Reach—uptake by target population; - Effectiveness—patient outcomes, cost-effectiveness; - Adoption—uptake by clinical staff (eg, participation in delivery, referrals); - Implementation—consistency and fidelity; - Maintenance—sustainability
Timing | Any duration
Setting | Any outpatient setting (including telehealth or mobile technology) in US, UK, Ireland, Canada, or Australia | Integrated healthcare delivery systems, outpatient setting (including telehealth or mobile technology) in US, UK, Ireland, Canada, or Australia
Study Design | RCTs or observational studies
Other | English language

| EXCLUSION CRITERIA
Populations | End-of-life (in hospice and/or ≤6 mo life expectancy); pain caused by advanced stage cancer (eg, bone metastases); receiving urgent or acute medical therapy for pain-causing condition (eg, chemotherapy, radiation, or surgery)
Interventions | Yoga, Taichi, Qigong
Settings | Acute care (ie, emergency rooms and inpatient floors) or institutional settings (eg, nursing homes)
Study Design | Reviews, study protocols, editorials, case reports