# APPENDIX A SEARCH STRATEGIES

## MEDLINE AND EMBASE

1 | (barrier$1 or facilitat* or intervention$1 or audit* or feedback or academic detail$1 or implement* adj3 (intervention* or model* or plan* or process* or strateg* or system*) or approach* adj3 (collaborative or complementary or comprehensive or innovative or integrated) or Treatment uptake or intervention uptake or referral practice* or treatment preference* or engagement or disseminat* or adopt* or sustain* or acceptance or acceptability or feasibility or attitude* or Incentive structure* or allowance structure* or accreditation or plan do study act or needs assessment or learning collaborat* or credentialing or licensure or implementation blueprint or quality monitor* or resource sharing or champions or early adopters or opinion leaders or network weaving or local technical assistance or scale up or train*).ti,ab,kw
2 | Practice patterns, physicians/ or attitude of health personnel/ or health services accessibility/ or patient acceptance of health care/ or clinical decision-making/ or physician-patient relations/ or patient participation/ or Reimbursement, Incentive/ or accreditation/ or needs assessment/ or credentialing/
3 | 1 or 2 (All implementation terms)
4 | (veteran or veterans).ti,ab,kw
5 | Veterans/ or Veterans Health/ or United States Department of Veterans Affairs/
6 | 4 or 5 (all veteran terms)
7 | Integrated delivery system*.ti,ab,kw
8 | Delivery of health care, integrated/
9 | 7 or 8 (all integrated delivery system terms)
10 | 6 or 9 (combined veteran and integrated delivery terms)
11 | ((chronic adj2 pain) or (pain and (musculoskeletal or (low adj back) or neck or shoulder or hip or knee or joint))).ti, ab, kw
12 | Chronic Pain/ or low back pain/ or shoulder pain/ or back pain/ or musculoskeletal pain/ or neck pain/
13 | 11 or 12 (all pain terms)
14 | ((CBT or cognitive behavioral therap* or cognitive therap* or prolonged exposure therap* or cognitive processing therap* or problem?solving t* or cognitive psychotherapy* or ACT or (acceptance commitment therap*) or MBSR or (mindfulness?based stress reduction) or mindful* or meditat* or (psychological adj1 therap*) or (behavioral adj1 therap*)) or DBT or dialectical behavior* therap* or family therap* or couples therap* or implosive therap* or mind-body therap* or interpersonal therap* or contingency management or social skills training or motivational enhancement therap* or present?centered t*).ti,ab,kw
15 | Cognitive Behavioral Therapy/ or Mind-Body Therapies/ or Implosive Therapy/ or Dialectical Behavior Therapy/ or Family Therapy/ or Couples Therapy/ or Implosive Therapy / or interpersonal psychotherapy/
16 | 14 or 15 (all intervention terms)
17 | 3 and 10 and 16 (Implementation terms, intervention terms, and veteran/integrated care terms)
18 | 3 and 13 and 16 (implementation terms, intervention terms, and pain terms)
19 | 17 or 18 (implementation and intervention terms with veteran/integrated delivery or pain terms)
20 | Limit 19 to English language

## CINAHL

1 | barrier$1 or facilitat* or intervention$1 or audit* or feedback or “academic detail$1” or implement* N3 (intervention* or model* or plan* or process* or strateg* or system*) or approach* N3 (collaborative or complementary or comprehensive or innovative or integrated) or “Treatment uptake” or “intervention uptake” or “referral practice*” or “treatment preference*” or engagement or disseminat* or adopt* or sustain* or acceptance or acceptability or feasibility or attitude* or “Incentive structure*” or “allowance structure*” or accreditation or “plan do study act” or “needs assessment” or “learning collaborat*” or credentialing or licensure or “implementation blueprint” or quality monitor* or “resource sharing” or champions or “early adopters” or “opinion leaders” or “network weaving” or “local technical assistance” or “scale up or train*”)
2 | (MH "Practice Patterns") or (MH "Attitude of Health Personnel") or (MH "Health Services Accessibility+") or (MH "Decision Making, Clinical+") or (MH "Physician-Patient Relations") or (MH "Consumer Participation") or (MH "Reimbursement, Incentive") (MH "Accreditation+") or (MH "Needs Assessment") or (MH "Credentialing+")
3 | 1 or 2 (All implementation terms)
4 | veteran or veterans
5 | (MH "Veterans+") or (MH "Veterans Health Services") or (MH "Hospitals, Veterans") or (MH "United States Department of Veterans Affairs")
6 | 4 or 5 (all veteran terms)
7 | Integrated delivery system*
8 | (MH "Health Care Delivery, Integrated")
9 | 7 or 8 (all integrated delivery system terms)
10 | 6 or 9 (combined veteran and integrated delivery terms)
11 | (“chronic N2 pain”) or “musculoskeletal pain” (“low N1 back pain”) or “neck pain” or “shoulder pain” or “hip pain” or “knee pain” or “joint pain”
12 | (MH "Chronic Pain") or (MH "Low Back Pain") or (MH "Shoulder Pain") or (MH "Back Pain+") or (MH "Neck Pain")
13 | 11 or 12 (all pain terms)
14 | CBT or “cognitive behavioral therap*” or “cognitive therap*” or “prolonged exposure therap*” or “cognitive processing therap*” or “problem#solving t*” or “cognitive psychotherapy*” or ACT or “acceptance commitment therap*” or MBSR or “mindfulness#based stress reduction” or mindful* or meditat* or “psychological N1 therap*” or “behavioral N1 therap* or DBT or “dialectical behavior* therap*” or “family therap*” or “couples therap*” or “implosive therap*” or “mind-body therap*” or “interpersonal therap*” or “contingency management” or “social skills training” or “motivational enhancement therap*” or “present# centered t*”
15 | (MH "Cognitive Therapy+") or (MH "Mind Body Techniques+") or (MH "Behavior Therapy+") or (MH "Dialectical Behavior Therapy") or (MH "Family Therapy") or (MH "Couples Counseling") or (MH "Interpersonal Psychotherapy")
16 | 14 or 15 (all intervention terms)
17 | 3 and 10 and 16 (Implementation terms, intervention terms, and veteran/integrated care terms)
18 | 3 and 13 and 16 (implementation terms, intervention terms, and pain terms)
19 | 17 or 18 (implementation and intervention terms with veteran/integrated delivery or pain terms)
20 | Limit 19 to English language

## PSYCINFO

1 | (barrier$1 or facilitat* or intervention$1 or audit* or feedback or academic detail$1 or implement* adj3 (intervention* or model* or plan* or process* or strateg* or system*) or approach* adj3 (collaborative or complementary or comprehensive or innovative or integrated) or Treatment uptake or intervention uptake or referral practice* or treatment preference* or engagement or disseminat* or adopt* or sustain* or acceptance or acceptability or feasibility or attitude* or Incentive structure* or allowance structure* or accreditation or plan do study act or needs assessment or learning collaborat* or credentialing or licensure or implementation blueprint or quality monitor* or resource sharing or champions or early adopters or opinion leaders or network weaving or local technical assistance or scale up or train*).ti,ab,hw,id
2 | Practice patterns, physicians/ or exp Health Personnel Attitudes/ or health services accessibility/ or patient acceptance of health care/ or clinical decision-making/ or physician-patient relations/ or exp Client Participation/ or Reimbursement, Incentive/ or accreditation/ or exp Needs Assessment/ or credentialing/
3 | 1 or 2 (All implementation terms)
4 | (veteran or veterans).ti,ab,hw,id
5 | exp Military Veterans/ or Veterans Health/ or United States Department of Veterans Affairs/
6 | 4 or 5 (all veteran terms)
7 | Integrated delivery system*.ti,ab,hw,id
8 | Delivery of health care, integrated/
9 | 7 or 8 (all integrated delivery system terms)
10 | 6 or 9 (combined veteran and integrated delivery terms)
11 | ((chronic adj2 pain) or (pain and (musculoskeletal or (low adj back) or neck or shoulder or hip or knee or joint))).ti,ab,hw,id
12 | Chronic Pain/ or low back pain/ or shoulder pain/ or exp Back Pain/ or musculoskeletal pain/ or neck pain/
13 | 11 or 12 (all pain terms)
14 | ((CBT or cognitive behavioral therap* or cognitive therap* or prolonged exposure therap* or cognitive processing therap* or problem?solving t* or cognitive psychotherapy* or ACT or (acceptance commitment therap*) or MBSR or (mindfulness?based stress reduction) or mindful* or meditat* or (psychological adj1 therap*) or (behavioral adj1 therap*)) or DBT or dialectical behavior* therap* or family therap* or couples therap* or implosive therap* or mind-body therap* or interpersonal therap* or contingency management or social skills training or motivational enhancement therap* or present?centered t*).ti,ab,hw,id
15 | exp Cognitive Behavior Therapy/ or exp Mind Body Therapy/ or exp Implosive Therapy/ or exp Dialectical Behavior Therapy/or exp Family Therapy/ or exp Couples Therapy/or exp Implosive Therapy/ or exp Interpersonal Psychotherapy/
16 | 14 or 15 (all intervention terms)
17 | 3 and 10 and 16 (Implementation terms, intervention terms, and veteran/integrated care terms)