# REFERENCES

1 Mahan CM, Page WF, Bullman TA, Kang HK. Health effects in Army Gulf War veterans possibly exposed to chemical munitions destruction at Khamisiyah, Iraq: Part I, morbidity associated with potential exposure. Mil Med. 2005;170(11):935–944.16450821
2 Page WF, Mahan CM, Kang HK, Bullman TA. Health effects in Army Gulf War veterans possibly exposed to chemical munitions destruction at Khamisiyah, Iraq: Part II. Morbidity associated with notification of potential exposure. Mil Med. 2005;170(11):945–51.16450822
3 McDiarmid MA, Engelhardt SM, Dorsey CD, . Longitudinal health surveillance in a cohort of Gulf War veterans 18 years after first exposure to depleted uranium. J Toxicol Environ Health A. 2011;74(10):678–91.21432717
4 National Academies. Respiratory Health Effects of Airborne Hazards Exposures in the Southwest Asia Theater of Military Operations. 2020. Washington DC: National Academies Press.270.
5 Department of Veterans Affairs. Public Health. [Website] Vietnam War Exposures. Available at: https://www.publichealth.va.gov/exposures/wars-operations/vietnam-war.asp. Accessed March 27, 2024.
6 Ahmed ST, Steele L, Richardson P, . Association of Gulf War Illness-Related Symptoms with Military Exposures among 1990–1991 Gulf War Veterans Evaluated at the War-Related Illness and Injury Study Center (WRIISC). Brain Sci. 2022;12(3).
7 Department of Veterans Affairs. Public Health. [Website] Gulf War Exposures. Available at: https://www.publichealth.va.gov/exposures/gulfwar/sources/index.asp. Accessed March 27, 2024.
8 Department of Veterans Affairs. Public Health. [Website] Iraq War Exposures. Available at: https://www.publichealth.va.gov/exposures/wars-operations/iraq-war.asp. Accessed March 27, 2024.
9 Department of Veterans Affairs. Public Health. [Website] Operation Enduring Freedom Exposures. Available at: https://www.publichealth.va.gov/exposures/wars-operations/oef.asp. Accessed March 27, 2024.
10 Department of Veterans Affairs. Public Health. [Website] Camp Lejeune: Past Water Contamination. Available at: https://www.publichealth.va.gov/exposures/camp-lejeune/. Accessed March 27, 2024.
11 National Academies. Gulf War and Health Volume 11: Generational Health Effects of Serving in the Gulf War. Copyright 2018 by the National Academy of Sciences. All rights reserved.
12 Department of Veterans Affairs. PACT Act Performance Dashboard. [Website] Available at: https://department.va.gov/pactdata/. Accessed March 27, 2024.
13 U.S. Senate. Sergeant First Class Heath Robinson Honoring our Promise to Address Comprehensive Toxics Act of 2022.
14 Mager Stellman J, Stellman SD, Sommer Jr JF. Social and behavioral consequences of the Vietnam experience among American Legionnaires. Environ Res. 1988;47(2):129–149.3263268
15 Goldman SM, Weaver FM, Stroupe KT, . Risk of Parkinson Disease Among Service Members at Marine Corps Base Camp Lejeune. JAMA Neurology. 2023;80(7):673–681.37184848
16 Sullivan GM, Feinn R. Using Effect Size-or Why the P Value Is Not Enough. J Grad Med Educ. 2012;4(3):279–82.23997866
17 Barrett DH, Morris RD, Jackson Jr WG, Michalek JE. Serum dioxin and psychological functioning in U.S. Air Force veterans of the Vietnam War. Mil Med. 2003;168(2):153–159.12636146
18 DeBeer BB, Davidson D, Meyer EC, . The Association Between Toxic Exposures and Chronic Multisymptom Illness in Veterans of the Wars of Iraq and Afghanistan. J Occup Environ Med. 2017;59(1):54–60.28045798
19 Hardos JE, Whitehead LW, Han I, . Depression Prevalence and Exposure to Organophosphate Esters in Aircraft Maintenance Workers. Aerosp. 2016;87(8):712–7.
20 Karami GR, Ameli J, Roeintan R, . Impacts of mustard gas exposure on veterans mental health: A study on the role of education. Ind Psychiatry J. 2013;22(1):22–5.24459369
21 King LA, King DW, Bolton EE, . Risk factors for mental, physical, and functional health in Gulf War veterans. J Rehabil Res Dev. 2008;45(3):395–407.18629748
22 Krengel MH, Zundel CG, Heeren T, . Health symptom trajectories and neurotoxicant exposures in Gulf War veterans: the Ft. Devens cohort. Environ Health. 2022;21(1):7.34998396
23 Kroenke K, Koslowe P, Roy M. Symptoms in 18,495 Persian Gulf War veterans. Latency of onset and lack of association with self-reported exposures. J Occup Environ Med. 1998;40(6):520–8.9636932
24 Lange JL, Schwartz DA, Doebbeling BN, . Exposures to the Kuwait oil fires and their association with asthma and bronchitis among gulf war veterans. Environ Health Perspect. 2002;110(11):1141–6.12417486
25 Mohaghegh-Motlagh SJ, Arab A, Momtazi S, . Psychological assessment of chemical injured war veterans compared to non-chemical injured war veterans. Asia-Pacific Psychiatry. 2012;4(3):189–194.
26 Robinowitz R, Roberts W, Dolan MP, . Carcinogenicity and teratogenicity vs. psychogenicity: Psychological characteristics associated with self-reported Agent Orange exposure among Vietnam combat veterans who seek treatment for substance abuse. J Clin Psychol. 1989;45(5, Mono Suppl):718–728.2808727
27 Safi-Aghdam H, Shafie M, Khoshdel A, . Long-term effects of chemical warfare on post-traumatic stress disorder, depression, and chronic medical conditions in veterans. Community Ment Health J. 2018.
28 Shapiro SE, Lasarev MR, McCauley L. Factor analysis of Gulf War illness: what does it add to our understanding of possible health effects of deployment? Am J Epidemiol. 2002;156(6):578–85.12226005
29 Yee MK, Zundel CG, Maule AL, . Longitudinal Assessment of Health Symptoms in Relation to Neurotoxicant Exposures in 1991 Gulf War Veterans: The Ft. Devens Cohort. J Occup Environ Med. 2020;62(9):663–668.32890202
30 White RF. Neuropsychological function in Gulf War veterans: relationships to self-reported toxicant exposures. Am J Ind Med. 2001;40(1):42–54.11439396
31 Khateri S, Soroush M, Mokhber N, . Mental health status following severe sulfur mustard exposure: a long-term study of Iranian war survivors. Asia Pac Psychiatry. 2017;9(2).
32 Martinez S, Yaffe K, Li Y, . Agent Orange exposure and dementia diagnosis in US veterans of the Vietnam era. JAMA Neurology. 2021;78(4):473–477.33492338
33 McCauley LA, Lasarev M, Sticker D, . Illness experience of Gulf War veterans possibly exposed to chemical warfare agents. Am J Prev Med. 2002;23(3):200–6.12350453
34 Decoufle P, Holmgreen P, Boyle CA, Stroup NE. Self-reported health status of Vietnam veterans in relation to perceived exposure to herbicides and combat. Am J Epidemiol. 1992;135(3):312–23.1546707
35 Hotopf M, David A, Hull L, . Risk factors for continued illness among Gulf War veterans: A cohort study. Psychol Med. 2004;34(4):747–754.15099428
36 Lindem K, Heeren T, White RF, . Neuropsychological performance in Gulf War era veterans: Traumatic stress symptomatology and exposure to chemical-biological warfare agents. J Psychopathol Behav Assess. 2003;25(2):105–119.
37 Unwin C, Blatchley N, Coker W, . Health of UK servicemen who served in Persian Gulf War. Lancet. 1999;353(9148):169–78.9923871
38 Zundel C, Price K, Grasso C, . The impact of neurotoxicant exposures on posttraumatic stress disorder trajectories: the Ft. Devens Gulf War Veterans Cohort. J Trauma Stress. 2022.
39 Smith TC, Wingard DL, Ryan MA, . PTSD prevalence, associated exposures, and functional health outcomes in a large, population-based military cohort. Public Health Rep. 2009;124(1):90–102.
40 Yi SW, Ohrr H, Hong JS, Yi JJ. Agent Orange exposure and prevalence of self-reported diseases in Korean Vietnam veterans. J Prev Med Pub Health. 2013;46(5):213–25.24137524
41 Barth SK, Kang HK, Bullman T. All-Cause Mortality Among US Veterans of the Persian Gulf War: 13-Year Follow-up. Public Health Rep. 2016;131(6):822–830.28123229
42 Boyd KC, Hallman WK, Wartenberg D, . Reported exposures, stressors, and life events among Gulf War Registry veterans. J Occup Environ Med. 2003;45(12):1247–56.14665810
43 Maupin GM, Tvaryanas AP, White ED, Mahaney HJ. Assessment of deployment-related exposures on risk of incident mental health diagnoses among Air Force Medical Service personnel: Nested case-control study. Mil Med. 2018;183(3–4):e123–e132.29514347
44 Smith TC, Gray GC, Weir JC, . Gulf War veterans and Iraqi nerve agents at Khamisiyah: postwar hospitalization data revisited. Am J Epidemiol. 2003;158(5):457–67.12936901
45 Gray GC, Smith TC, Knoke JD, Heller JM. The postwar hospitalization experience of Gulf War Veterans possibly exposed to chemical munitions destruction at Khamisiyah, Iraq. Am J Epidemiol. 1999;150(5):532–40.10472954
46 Smith TC, Heller JM, Hooper TI, . Are Gulf War veterans experiencing illness due to exposure to smoke from Kuwaiti oil well fires? Examination of Department of Defense hospitalization data. Am J Epidemiol. 2002;155(10):908–17.11994230
47 Stuart JA, Ursano RJ, Fullerton CS, . Belief in Exposure to Terrorist Agents: Reported Exposure to Nerve or Mustard Gas by Gulf War Veterans. J Nerv Ment Dis. 2003;191(7):431–436.12891089
48 Tvaryanas AP, Maupin GM, Fouts BL. Assessment of deployment-related exposures on risk of incident mental health diagnoses among Air Force critical care providers: Nested case-control study. Mil Med. 2016;181(2):143–151.26837083
49 Proctor SP, Heeren T, White RF, . Health status of Persian Gulf War veterans: self-reported symptoms, environmental exposures and the effect of stress. Int J Epidemiol. 1998;27(6):1000–10.10024195
50 Steele L, Sastre A, Gerkovich MM, Cook MR. Complex factors in the etiology of Gulf War illness: wartime exposures and risk factors in veteran subgroups. Environ Health Perspect. 2012;120(1):112–8.21930452
51 Hotopf M, David AS, Hull L, . The health effects of peace-keeping in the UK Armed Forces: Bosnia 1992-1996. Predictors of psychological symptoms. Psychol Med. 2003;33(1):155–162.12537046
52 Krengel M, Sullivan K, Heboyan V, . Neurotoxicant exposures and rates of Chronic Multisymptom Illness and Kansas Gulf War Illness criteria in Gulf War deployed women veterans. Life Sci. 2021;280:119623.34004246
53 Nisenbaum R, Barrett DH, Reyes M, Reeves WC. Deployment stressors and a chronic multisymptom illness among Gulf War veterans. J Nerv Ment Dis. 2000;188(5):259–266.10830562
54 Powell TM, Smith TC, Jacobson IG, . Prospective assessment of chronic multisymptom illness reporting possibly associated with open-air burn pit smoke exposure in Iraq. J Occup Environ Med. 2012;54(6):682–8.22684320
55 Barrett DH, Morris RD, Akhtar FZ, Michalek JE. Serum dioxin and cognitive functioning among veterans of Operation Ranch Hand. Neurotoxicology. 2001;22(4):491–502.11577806
56 Chao L. Do Gulf War veterans with high levels of deployment-related exposures display symptoms suggestive of Parkinson’s disease? Int J Occup Med Environ Health. 2019;32(4):503–526.31309787
57 Haley RW, Kurt TL. Self-reported exposure to neurotoxic chemical combinations in the Gulf War. A cross-sectional epidemiologic study. JAMA. 1997;277(3):231–7.9005273
58 Spencer PS, McCauley LA, Lapidus JA, . Self-reported exposures and their association with unexplained illness in a population-based case-control study of Gulf War veterans. J Occup Environ Med. 2001;43(12):1041–56.11765675
59 Toomey R, Alpern R, Vasterling JJ, . Neuropsychological functioning of U.S. Gulf War veterans 10 years after the war. J Int Neuropsychol Soc. 2009;15(5):717–729.19640317
60 Wolfe J, Proctor SP, Davis JD, . Health symptoms reported by Persian Gulf War veterans two years after return. Am J Ind Med. 1998;33(2):104–13.9438043
61 Wolfe J, Proctor SP, Erickson DJ, Hu H. Risk factors for multisymptom illness in US Army veterans of the Gulf War. J Occup Environ Med. 2002;44(3):271–81.11911029
62 Inoue C, Shawler E, Jordan CH, . Veteran and Military Mental Health Issues. StatPearls. 2024.
63 US Department of Veterans Affairs. National Strategy for Preventing Veteran Suicide 2018–2028. 2018.
64 Department of Veterans Affairs. VA has screened 5 million Veterans for toxic exposures, paving the way for early detection and treatment of health conditions. [News article, December 12, 2023] Available at: https://news.va.gov/press-room/va-screens-5-million-veterans-toxic-exposures/. Accessed April 11, 2024.
65 American Psychiatric Association. The Structured Clinical Interview for DSM-5®. Available at: https://www.appi.org/products/structured-clinical-interview-for-dsm-5-scid-5. Accessed April 11, 2024.
66 Department of Veterans Affairs. One year of the PACT Act: A historic expansion of benefits and health care for Veterans and their survivors. [News article, August 10, 2023]. Available at: https://news.va.gov/press-room/one-year-of-pact-act-a-historic-expansion-of-benefits-and-health-care-for-veterans-and-their-survivors/. Accessed April 11, 2024.
67 Schaeffer K. The changing face of America’s veteran population. Pew Research Center. 2023. Available at: https://www.pewresearch.org/short-reads/2023/11/08/the-changing-face-of-americas-veteran-population/. Accessed April 11, 2024.
68 Barroso A. The changing profile of the U.S. military: Smaller in size, more diverse, more women in leadership. Available at: https://www.pewresearch.org/short-reads/2019/09/10/the-changing-profile-of-the-u-s-military/. Accessed April 11, 2024.
69 Bourassa KJ, Wagner HR, Halverson TF, . Deployment-related toxic exposures are associated with worsening mental and physical health after military service: Results from a self-report screening of veterans deployed after 9/11. J Psychiatr Res. 2024;174:283–288.38678685
70 Baiocchi M, Cheng J, Small DS. Instrumental variable methods for causal inference. Stat Med. 2014;33(13):2297–340.24599889
71 Sanderson E, Glymour MM, Holmes MV, . Mendelian randomization. Nat Rev Methods Primers. 2022;2.
72 Turkheimer E, Harden KP. Behavior Genetic Research Methods: Testing Quasi-Causal Hypotheses Using Multivariate Twin DataAvailable at: https://labs.la.utexas.edu/harden/files/2013/05/Turkheimer-Harden-2014-Handbook.pdf. Accessed April 11, 2024.
73 McGue M, Osler M, Christensen K. Causal Inference and Observational Research: The Utility of Twins. Perspect Psychol Sci. 2010;5(5):546–56.21593989
74 Cohen DE, Sullivan KA, McNeil RB, . A common language for Gulf War Illness (GWI) research studies: GWI common data elements. Life Sci. 2022;290:119818.34352259