# ACKNOWLEDGMENTS

The authors are grateful to Dr. Stacy Lavin, Liz Wing and Lauren Ramsdell for editorial support, Dr. Eric Monson and Dr. Nicholas J. Parr for data visualization expertise, Kaitlyn Goodwin for data curation help, and the external peer reviewers. This work was partially supported by the Durham Center of Innovation to Accelerate Discovery and Practice Transformation (ADAPT) (CIN 13-410) at the Durham VA Health Care System. The authors are also grateful for the contributions of the following individuals:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Jennifer Patterson, PhD, ABPP
  National Director, Integrated Services
  VHA Office of Mental Health and Suicide Prevention

## Technical Expert Panel

To ensure robust, scientifically relevant work, the technical expert panel (TEP) guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members included:

- Clifford A. Smith, PhD
  Director Analytics, Innovations, and Collaborations
  Office of Mental Health & Suicide Prevention

- Heather Young, PhD
  Professor in Epidemiology and Environmental Health
  George Washington University

- Stephen C. Hunt, MD
  Director
  Deployment Health Clinic
  Puget Sound VA

- Lisa McAndrew, PhD
  Primary Investigator
  War Related Illness and Injury Study Center,
  New Jersey VA

- Douglas C. Johnson, PhD
  Neuropsychologist
  Missouri VA

- Kyla Taylor, PhD
  Health Scientist
  Integrative Health Assessment, Division of Translational Toxicology National Institute of Environmental Health Sciences (NIEHS)