# Executive Summary

KEY FINDINGS

► Forty-nine studies provide evidence on the association between toxic exposures during military service and psychiatric or neurocognitive outcomes.
► Chemical exposures, including chemical munitions from the Gulf War era and Agent Orange from the Vietnam War era, were the most frequently examined military toxic exposures.
► Depression and PTSD symptoms were the most commonly reported psychiatric outcomes. Few studies reported on other important psychiatric outcomes, such as suicidality and substance misuse. Only 9 studies assessed neurocognitive functioning as a standalone outcome, making it difficult to discern the impact of military toxic exposures on cognition outcomes.
► Notable gaps in the current literature include:
  ○ Camp Lejeune contaminated water, radiation, and heavy metals are understudied military toxic exposures.
  ○ Little is known about women Veterans and those from underrepresented racial and ethnic groups.
  ○ The need for more research examining mental health outcomes associated with exposure during the Vietnam and the post-9/11 period of military deployment and service.
  ○ Better understanding of the association of military toxic exposures with objective neuropsychological outcomes.
► There were a few notable patterns in the strength of associations between military toxic exposures and psychological diagnoses.
  ○ Large to moderate associations were frequently observed between PTSD symptoms and chemical exposures, smoke from oil fires and burn pits, and multiple/mixed exposure types.
  ○ A small body of literature (3 studies) suggests a moderate to strong association pattern between military-related Agent Orange exposures for Vietnam-era Veterans and psychotic disorders and psychosis symptoms.
► Despite multiple gaps in the current literature, available evidence suggests that Veterans with a high likelihood of environmental toxic exposures during military service would be expected to later present with relatively high levels of mental health needs.

Across all military eras, U.S. service members have been exposed to toxic biological and chemical agents (eg, pesticides, herbicides, chemical weapons), airborne hazards (eg, burn pits, diesel fumes), depleted uranium and other radioactive materials, and several other hazards. Yet the prevalence of psychiatric conditions and symptoms among those with military toxic exposures has been poorly understood. The Sergeant First Class (SFC) Heath Robinson Honoring Our Promise to Address Comprehensive Toxics (PACT) Act expands and extends VA health care eligibility for Veterans with conditions presumed to be caused by military toxic exposures. This expansion in VA benefits will likely lead to an increase in Veterans with presumed toxic exposures accessing VA care. Understanding what resources may be needed to support Veteran patients receiving mental health services can inform future planning of health care services and delivery. An evidence map on this topic will be used to assist Veterans Health Administration (VHA) clinical teams in providing evidence-informed care to Veterans who present with psychiatric concerns during toxic exposure screenings and in developing national guidance for approaches to screening, assessment, and treatment related to these concerns.

## CURRENT REVIEW

### Data Sources and Searches

We searched MEDLINE (via Ovid), Embase (via Elsevier), APA PsycINFO (via Ovid), and PTSDpubs (via ProQuest) through July 27, 2023. We used database-specific controlled vocabulary as well as relevant keywords to search titles and abstracts. Additional citations were identified from hand-searching reference lists and consultation with content experts. Titles, abstracts, and full-text articles were independently reviewed by 2 investigators, and disagreements were resolved by consensus.

### Study Selection

In brief, eligibility was limited to studies that examined the associations between environmental exposures that occurred during military service and psychiatric or neurocognitive diagnoses or symptoms. Studies were also required to include at least 100 Veteran participants. We excluded studies if they focused only on exposures that occurred while not serving in the armed forces. We also excluded studies focused on pyridostigmine bromide (PB) pills or vaccinations given during military service.

We screened all identified citations in duplicate by human reviewers at the title, abstract, and full-text level. Citations meeting eligibility criteria were included for data abstraction. Disagreement was resolved via group consensus or by a senior investigator with content or methodological expertise.

### Data Abstraction

Data elements included details of the study populations, exposure types, and outcomes (including measurement methods). Because most studies reported little or no information about exposure route, we grouped similar exposure types unless the route was explicitly described. To categorize mental health symptoms and conditions, we relied on the definitions used in primary studies as well as existing categories used withing the VHA, whenever possible. We acknowledge that similar symptoms are commonly experienced across multiple conditions, and that there are likely multiple ways that mental health outcomes and toxic exposures could have been categorized.

### Synthesis

Given the heterogeneity in mental health outcomes, we organized our results into 3 broad categories: psychiatric diagnoses (eg, PTSD), psychiatric symptoms (eg, feeling nervous and tense), and neurocognitive functioning (eg, memory/learning, attention/concentration). We summarized key study characteristics of the included studies including participant descriptors (eg, race, sex), exposure characteristics (eg, type, dose, assessment), and mental health outcomes organized by the 3 categories.

To map patterns across the included studies, we abstracted effect sizes when possible, and categorized the magnitude of the effect as none, small, medium, or large.

- When a single study reported more than 1 measured association between the same exposure and outcome, we counted effect sizes (eg, 2 none vs 1 small vs 4 large) and prioritized the most common effect size (eg, large).
- If there was more than 1 exposure level (eg, 2 vs 6 days), we counted effect sizes within the most extreme exposure level (eg, highest number of days = 6 days) and used the most commonly occurring association for that exposure level as the magnitude of the effect estimate.
- While not commonly reported, when there were different routes of exposure (eg, inhalation, skin absorption), each route of toxic exposure was considered a unique toxic exposure.

## RESULTS

### Results of Literature Search

Of 1,929 unique citations, our search identified 161 potentially relevant articles after title and abstract screening. Of these, 49 primary studies met eligibility criteria. Only 41 were relevant to KQ2 (ie, reported disaggregated psychiatric or neurocognitive outcomes). Seventeen studies reported neurocognitive symptoms, diagnosis, or measures; 19 studies reported psychiatric diagnoses; and 30 reported psychiatric symptoms. Most of the included studies (N = 29) were conducted among Persian Gulf War Veterans. Seven studies reported on exposures from the Vietnam War era, 5 studies reported Iraq War exposures, 4 among Iran-Iraq conflict exposures, and 3 among Afghanistan War exposures. Remaining studies reported other eras of service (N = 2), did not report a specific era of service (N = 1), or were peacetime exposures (N =1). Four studies included Veterans from more than 1 specific era of military service. Studies that reported sociodemographic composition of the study samples enrolled mostly male participants (range: 76%-100%) and were 65% or more White. Ethnicity was very rarely reported. There was extensive variation in how exposures and outcomes were defined and measured across studies; details about exposure or route or duration were rarely reported. Many studies only used one item from a multi-item health questionnaire to capture complex mental health constructs and most data were based on self-reports.

### Summary of Results for Key Questions

#### KQ1 Evidence Mapping of Symptoms and Diagnosis

- Nearly half of studies (N = 21) examined depression symptoms or diagnoses associated with military toxic exposures. The most frequently reported exposures were chemical weapons (N = 9) and pesticides (N =3), including 2 additional studies of Agent Orange. The least frequently reported exposure was Camp Lejeune contaminated water (N = 1).
- Eleven studies assessed anxiety symptoms and disorders. Nine examined chemical exposures which included Agent Orange (N = 2) or chemical weapons (N = 7). Others examined tent heater exhaust (N = 1) and Camp Lejeune contaminated water (N = 1).
- Fifteen studies examined PTSD symptoms and diagnoses associated with exposure to chemicals as the most common: chemical weapons (N = 9), herbicides (N = 3), pesticides (N = 3), various other chemicals such as paint and solvents (N = 3). Other exposures included burn pits (N = 2), oil well fires and exhaust from heaters and generators (N = 1), depleted uranium (N = 1) and multiple exposures (N = 3), or other exposures such as diesel fuel (N = 1).
- Nine studies assessed sleep dysfunction or sleep disorders. The most frequently reported exposures were chemical weapons (N = 4) and pesticides (N = 2). One study explored sleep disorders among Veterans exposed to contaminated water at Camp Lejeune.
- Four studies assessed psychotic disorders and symptoms of psychosis; the most common exposure was Agent Orange (N = 3).
- Substance use was examined only in 6 studies, with the most common exposure being Agent Orange (N = 4).
- A single study examined the association between death by suicide and a military toxic exposure (the Khamisiyah munitions depot explosion).
- The relationship between toxic exposures and neurocognitive functioning was assessed by 22 studies; however, only 9 assessed neurocognition as a stand-alone outcome (ie, not combined with other psychological or physical symptoms/diagnoses). The most common exposure in these 9 studies was Agent Orange (N =3).

#### KQ2 Evidence Mapping of Prevalence, Incidence, and Association

In total, 41 of the included 49 studies provided information about the association between military-related toxic exposures and psychiatric symptoms and diagnosis or neurocognitive function. The remaining 8 studies reported composite outcomes of psychiatric symptoms or physical symptoms but did not provide separate analyses by neurocognitive or psychiatric outcomes. The figure below provides a visualization of the patterns in associations across mental health outcomes encompassed in these 41 studies.

- Available studies differed in how toxic exposures and mental health outcomes were defined and measured, making it difficult to identify patterns in associations between exposures and outcomes. Nonetheless, a few patterns were evident.
  ○ Across PTSD analyses, large and moderate effects were frequently observed in relation to chemical, smoke from oil fires and burn pits, and multiple/mixed exposure types.
  ○ Across several studies, herbicide and pesticide exposures had moderate and large strength associations with symptoms of anxiety.
  ○ While we identified only 3 studies that looked at the association between military-related Agent Orange exposures and psychotic disorders and psychosis symptoms, this small body of literature suggests a moderate-to-strong association pattern.
- Associations were rarely reported for neurocognitive symptoms and diagnoses, making it difficult to determine the strength of associations.

Size of Associations Across Most Common Exposures and Most Common Symptoms and Conditions

Note. This figure provides a visualization of the number of associations across studies cateogrized into effect sizes within outcome category, separated by 4 major groups of toxic exposures. Bubble size is an indication of relative number of measured associations reported in the included studies. The chemical category includes chemical exposures, chemical weapons, JP-8 and other diesel, pesticides, and herbicides (including Agent Orange).

### Discussion and Future Directions

Military service members have the potential to be exposed to various environmental and chemical toxic substances that have been documented to have serious physical health impacts. The PACT Act extends VA health care eligibility for Veterans with conditions presumed to be caused by military toxic exposures, including expanded eligibility for mental health and counseling services to Veterans who were in theater or potentially exposed to toxic agents during military service. At the same time, the extent of psychiatric or neurocognitive conditions and symptoms among those with military-related toxic exposures has been poorly understood. Clarity on this topic will assist the VHA in providing evidence-informed care to Veterans who present with psychiatric concerns during toxic exposure screenings and to develop national guidance for approaches to screening, assessment, and treatment related to these concerns.

Whether service-connected for toxic exposure or not, many Veterans who become connected to the VA in the coming decades will have mental health disorders, symptoms, and/or neuropsychiatric needs that VHA providers will be asked to meet. Although studies identified by this review are not able to confirm a direct causal relationship between military-related toxic exposures and adverse psychiatric or neurocognitive outcomes, available evidence does suggest that Veterans with a high likelihood of military toxic exposures are likely to present with relatively high levels of mental health needs.

We identified several potential areas for future research, largely centered on the diagnoses and symptoms that would benefit from future research (eg, self-harm and suicidality, psychiatric disorders, substance use, neurocognitive functioning as a distinct construct); expanding methods of assessing toxic exposure and more robust exploration of some exposures (eg, Camp Lejeune contaminated water, radiation, heavy metals); the utilization of existing VHA data; and the need to expand the methodologies, and populations included in the study of toxic exposure and mental health (eg, post-9/11 cohorts, women Veterans, underrepresented racial and ethnic groups).

## CONCLUSIONS

Our results highlight the psychological and neurocognitive symptoms and diagnoses that have more empirical evidence. Regarding the outcomes, the preponderance of literature has examined various types of chemical exposures, specifically chemical munitions, mainly from the Gulf War era, and herbicides (ie, Agent Orange from Vietnam era), with less information on other chemicals such as solvents and Camp Lejeune-related exposures. We identified little research on other exposures such as radiation and heavy metals. Future research should aim to incorporate multiple sources of data (eg, medical records, military records, and objective psychodiagnostic assessments) to increase the reliability and validity of exposure and diagnosis variables. Additionally, study samples that are more representative of the modern active-duty and Veteran populations are essential. To this end, studies that enroll more women, racially diverse participants, and Veterans deployed post-9/11 are needed to fully understand the impact of toxic exposures among Veterans served by the VA.