# DISCUSSION

Military service members have the potential to be exposed to various environmental and chemical toxic substances that have been documented to have serious physical health impacts. Yet it is unknown how prevalent the co-occurrence of psychiatric or neurocognitive conditions and symptoms are among those with military-related toxic exposures. The PACT Act extends VA health care eligibility for Veterans with conditions presumed to be caused by toxic exposure during military service, including expanded eligibility for mental health and counseling services to Veterans who were in theater or potentially exposed to toxic agents during military service.^13^ Yet it is unknown which military service-related environmental and chemical toxic exposures have been explored for the co-occurrence of psychiatric or neurocognitive concerns. Such information will assist the VHA in providing evidence-informed care to Veterans who present with psychiatric concerns during toxic exposure screenings and to develop national guidance for approaches to screening, assessment, and treatment related to these concerns. The goal of this report was not to synthesize effect estimate information through quantitative (ie, metanalysis) or qualitative (ie, narrative) methods but to describe the range of, and patterns within, these associations, when possible. As such, we conducted an evidence mapping to describe and characterize (1) where these associations have been explored, (2) the range of these associations, and (3) where there are gaps in the literature on these associations.

In total, we identified 49 studies that met our eligibility criteria. Of these, 41 reported psychiatric or neurocognitive outcomes relevant for KQ2, with most of these relationships being assessed for psychiatric concerns. Depression and PTSD symptoms were the most commonly reported psychiatric outcomes, which is not surprising given that these are the 2 most prevalent mental health conditions among post-deployed Veterans.^62^ Yet, we identified only 1 study that assessed self-harm or suicide,^41^ which is surprising as this is a major health concern among Veterans cared for though the VHA.^63^ We identified a paucity of information on other important mental health outcomes such as substance use and more severe mental health symptoms (eg, psychosis). Although 22 studies discussed the relationship between toxic exposures and neurocognitive functioning, only 9 of these assessed neurocognitive functioning as an independent construct, and much of the information we have on these limited outcomes did not specify the strength of associations. As such, it is unclear what the relationship is between neurocognitive functioning and military toxic exposures in most of the studies identified in our evidence mapping study.

Nearly half the studies were cross-sectional designs, which limits the ability to establish temporal precedence in the association between mental health and toxic exposure. Most included studies were conducted among Persian Gulf War Veterans. Relatively few studies explored mental health concerns of the most recent wars in Afghanistan and Iraq (ie, OEF, OIF, OND), and even fewer studies explored the mental health concerns of Veterans exposed to contaminated water at Camp Lejeune. Most associations across studies were on chemical exposures, with the largest proportion of these being chemical weapons followed by herbicides, most commonly Agent Orange among Vietnam-era Veterans. Notable gaps are exposures to burn pits and other air pollutants, Camp Lejeune contaminated water, heavy metals, or radiation across all mental health concerns. In terms of populations examined, there was an over-representation of individuals who identify as White and male, even when considering the sociodemographic makeup of the military since the Persian Gulf War era.

We also sought to characterize patterns in the strength of associations represented in the literature. It is important to note that we mapped these association patterns (ie, small, moderate, large) regardless of statistical significance of the point estimates, unless significance (yes vs no) was the only data provided on these associations. Overall, most of the data were too heterogeneous to assess patterns in the strength of association and, as noted above, there are many gaps between the exposures and mental health outcomes explored. Still, we observed a few distinct patterns. Across PTSD analyses, large and moderate effects were frequently observed among chemical, smoke from oil fires and burn pits, and multiple/mixed exposure types, although notable gaps remain for tests of Khamisiyah-related and Camp Lejeune contaminated water exposures. While we identified only 3 studies that looked at the association between military-related Agent Orange exposures and psychotic disorders and psychosis symptoms, this small body of literature suggests a moderate-to-strong association pattern. Effect sizes were rarely reported for neurocognitive outcomes, making it difficult to determine the strength of associations. No other common theme arose with regards to the pattern of exposure or strengths of association.

## LIMITATIONS

To improve the feasibility of our search strategy and to provide information most applicable to U.S. Veterans, we limited our review to studies that were conducted among military Veterans. While we included Veterans who served both for the U.S. and other nations, we did not include other civilian populations who may have experienced exposures like those in the military (eg, 9/11 first responders, commercial aircraft maintenance workers). Also, there are limitations to using an evidence mapping approach. Evidence mapping is used to describe and characterize a broad area of research and often employs visual displays to depict the breadth, variation, and gaps present in the universe of studies exploring a topic. Thus, we provided here a descriptive analysis of the characteristics of the literature we found. To inform decision-making, we also abstracted and summarized patterns in outcomes data, when reported. Yet we did not seek to synthesize these outcomes data into summary estimates. We also did not conduct a critical appraisal of the included studies. We sought only to describe the patterns in the strengths of these associations.

Existing research has several important limitations, including inconsistency in outcome and toxic exposure measurement. Subjective assessment (eg, self-reporting, questionnaires) appeared to be the most used method, with few studies statistically adjusting or considering the validity of the data. Many studies only used 1 item from a multi-item health questionnaire to capture complex constructs such as anxiety or sleep. Some studies used semi-structured interviews or record reviews (military and medical) to determine the diagnosis and exposure variables. Most of these studies assessed chemical exposures in relation to the Gulf War and Vietnam. There was a lack of information regarding route of exposure and quantity of exposure (eg, amount of toxin, length of exposure). Demographic data of participants was most often incomplete, but when reported almost always included a predominately White, male, midlife sample. Many of the studies employed a methodology that relied on participants to retrospectively endorse an exposure that may have happened a decade before the study occurred, increasing the risk of recall bias. Also many studies explored both multiple or mixed exposures and composite mental health diagnoses, making it difficult to discern what class of exposure or diagnosis was driving results.

## CLINICAL AND POLICY IMPLICATIONS

Despite these limitations, the results of this systematic evidence map have clinical and health policy implications relevant to the care of Veterans. Whether service-connected for toxic exposure or not, many Veterans who become connected to the VA in the coming decades will have mental health disorders, symptoms, and/or neuropsychiatric needs that VHA providers will be asked to meet.^64^

Although studies identified by this review are not able to confirm a direct causal relationship between military-related toxic exposures and adverse psychiatric or neurocognitive outcomes, available evidence does suggest that Veterans with a high likelihood of military toxic exposures are likely to present with relatively high levels of mental health needs. Moreover, in March 2024, the VA expanded VA health care under the PACT Act to 3 new cohorts of Veterans who were originally granted eligibility on a phased-in schedule. Thus, there is the potential for an immediate and urgent impact of the mental health needs of these newly service-connected individuals.

## AREAS FOR FUTURE RESEARCH

We identified several potential areas for future research, largely centered on the diagnoses and symptoms that would benefit from future research; expanding methods of assessing toxic exposure and more robust exploration of some exposures; the utilization of existing VHA data; and the need to expand the methodologies, and populations included in the study of toxic exposure and mental health. First, there were several psychological symptoms and diagnoses that were less well studied and might benefit from particular focus in future research. For example, mental health diagnostic status was limited in scope and assessment type. The literature would benefit from more use of gold-standard interview protocols (ie, Structured Clinical Interview for DSM-5, Research Version, SCID-5-RV^65^) and/or electronic medical record diagnostic data. In addition, non-clinical psychological measures, such as measures of subjective wellbeing, could be useful for future study. Integrating symptom and performance validity testing is also recommended to ensure the data are accurate. Similarly, utilizing objective neuropsychological measures would be helpful to better characterize associations between toxic exposure and neurocognitive status, behind subjective self-report. In addition, several mental health diagnoses and symptoms would benefit from additional study due to a limited amount of published research including anxiety disorders, sleep-wake symptoms and disorders, substance use disorders and symptoms, and suicidal thoughts and behaviors.

The results of our review suggest there is a gap in research using varied methods to assess both toxic exposure and standardization of measures assessing mental health and neuropsychological functioning. Although there are many ways to assess toxic exposure, ranging from direct measurement of tissue to GIS/GPS-localization and self-report, the studies we reviewed largely used self-report measures. Although there is great value in self-reports of exposure, including ease of assessment and the ability to assess exposures that might have occurred years in the past, it is notable that studies using other methods of assessing exposure were more limited. Future research of military exposures among Veterans would likely benefit from using validated methods of assessing toxic exposure. For example, Department of Defense records of vaccination or troop deployment could be integrated with electronic health record data to assess exposure and health outcomes. Similarly, the measurement of mental health and neuropsychological outcomes was highly heterogeneous across the studies reviewed, particularly in the case of neuropsychological testing. For example, most studies examining neurocognitive outcomes used subjective measures of cognition, rather than objective neuropsychological tests. More standardization across mental health outcomes would help facilitate future efforts to understand the associations between toxic exposure and mental health. The VHA continues to implement the 2022 PACT Act,^13,66^ and our findings highlight the need for expanded research into the exact prevalence of mental health disorders among the Veterans currently being screened. To date, more than 5 million Veterans have been screened over 13 months,^64^ representing almost a third of the total population.^67^ Notably, these screenings could be a valuable resource for future study, as they are accessible for research purposes in the VHA electronic medical record. Although studies relying exclusively on the results of these screenings could be limited in their ability to provide comprehensive mental health phenotypes, it might be possible to assess mental health diagnoses, mental health symptoms, and mental health service utilization through “big data” approaches that effectively leverage this data source.

There is a notable need for more research examining mental health outcomes associated with exposure during the most recent period of military deployment and service—the post-9/11 period. As the demographic makeup of the U.S. military has changed over time (eg, more socioeconomic diversity, more women, and more people from minoritized racial and ethnic groups),^68^ it is essential that future research examines this cohort directly, rather than relying exclusively on evidence from prior military periods or populations. Only 10% of the reviewed studies were focused on post-9/11 service samples, compared to the 56% focused explicitly on Veterans from the Gulf War cohort. Although many Veterans served during both periods, and both periods include similarities in possible toxic exposures, the weight of empirical evidence highlights the value in more future study of the mental health of Veterans who were exposed to toxins during the post-9/11 period. This is particularly relevant given the large number of these Veterans who will be engaged in VA services for many decades to come.

Finally, our evidence map suggests that future research on the toxic exposure and mental health outcomes would benefit from the application of more sophisticated methodological approaches. Many of the studies assessing military exposures and mental health outcomes were cross-sectional and did not assess change in mental health symptoms, particularly in the period after separation from the military. The mental health service needs of Veterans are likely to change over time as the most recent cohorts reach midlife and older age. More longitudinal studies examining the link between toxic exposure and changes in mental health outcomes would be critical to provide some context as to the future mental health service needs of the Veteran population over the next several decades. It is possible that the increased attention on toxic exposures within the VHA will help promote more longitudinal studies of this type in the future (see Bourassa et al, 2024^69^ for an example). Beyond the need for more longitudinal outcomes, almost all the empirical studies we reviewed were correlational. Future studies would benefit from the use of more sophisticated methods of casual inference. For example, instrumental variable approaches^70^ (eg, genetically informed Mendelian randomization^71^), twin studies,^72,73^ or quasi-causal natural experiment approaches would all be valuable in characterizing the association between toxic exposure and mental health among Veterans. Finally, several of the studies explored a large number of associations by studying batteries that included many toxic exposures and psychological outcomes. Although this level of granularity can be beneficial, some degree of data dimension reduction (ie, simplification) would be helpful. Whether combining exposures or using higher order factors of psychopathology, dimension reduction would improve the interpretability of study findings and reduce the chance for type I errors (ie, false-positives).

The findings highlight the clear need for future research to better characterize the mental health needs of Veterans exposed to toxins, particularly using standardized and validated measures. Institutional support to promote this research—whether through existing Office of Research & Development Military-Exposure Research Program funding lines, availability of new registry data, or the promotion of research centers—could help develop the empirical evidence linking toxic exposure and mental health, which would be a valuable resource to providers and health administrative officials serving Veterans with toxic exposure. For example, the establishment of common data elements that studies could include to support the study of toxic exposure and mental health could be helpful, in line with the Gulf War Illness Common Data Elements Project.^74^ Such efforts could provide data sources that support studies building an evidence base that can effectively answer questions relevant to clinical practice. New research could help provide context as to the service needs and characteristics of this subpopulation of Veterans.

## CONCLUSIONS

Our results highlight the psychological and neurocognitive symptoms and diagnoses that have more empirical evidence. Regarding the outcomes, the preponderance of literature has examined various types of chemical exposures, specifically chemical munitions, mainly from the Gulf War era, and herbicides (ie, Agent Orange from Vietnam era), with less information on other chemicals such as solvents and Camp Lejeune-related exposures. We identified little research on other exposures such as radiation and heavy metals. Future research should aim to incorporate multiple sources of data (eg, medical records, military records, and objective psychodiagnostic assessments) to increase the reliability and validity of exposure and diagnosis variables. Additionally, study samples that are more representative of the modern active-duty and Veteran populations are essential. To this end, studies that enroll more women, racially diverse participants, and Veterans deployed post-9/11 are needed to fully understand the impact of toxic exposures among Veterans served by the VA. While multiple gaps exist in the current literature, results suggest that Veterans who have a high probability of experiencing military toxic exposures are likely to present with relatively high levels of mental health needs that VHA providers will be asked to meet in the coming decades.