# RESULTS

## LITERATURE FLOW DIAGRAM

The literature flow diagram summarizes the results of the study selection process. A full list of excluded studies is provided in the Appendix.

## OVERVIEW OF INCLUDED STUDIES

Our search identified 1,929 unique citations. Of those, 161 potentially relevant articles remained after title and abstract screening. Of these, 49 primary studies met eligibility criteria. Of the 49 included studies, only 41 reported disaggregated psychiatric or neurocognitive outcomes relevant for KQ2. Seventeen studies reported neurocognitive symptoms, diagnosis, or measures; 19 studies reported psychiatric diagnoses; and 30 reported psychiatric symptoms. Table 4 shows an overview of the included studies. We present detailed study characteristics in the Appendix. In brief, the median sample size of included studies was 69,627 (range: 100–1,368,148). Thirteen studies were cohorts with control groups, 8 were cohorts without a control group, 5 were case-control, and 23 were cross-sectional. Most of the included studies (N = 29) were conducted among Persian Gulf War Veterans. Seven studies reported exposures from the Vietnam War era, 5 from Iraq War exposures, 4 from Iran-Iraq conflict exposures, and 3 from Afghanistan War exposures. Remaining studies reported other eras of service (N = 2), did not report a specific era of service (N = 1), or were peacetime exposures (N =1). Four studies included Veterans from more than 1 specific era of military service.

Table 4 Evidence Profile of Included Studies

Number of Studies | 49 unique (49 articles)
Key Question | KQ1 (N = 49); KQ2 (N = 41)
Study Designs | Cohort (control group^a^) (N = 13); cohort (no control group^a^) (N = 8); case-control (N = 5); cross-sectional (N = 23)
Study Year Range | 1988 to 2023
Median Number of Participants | 69,627 (range: 100 to 1,368,148)
Participant Country of Origin | USA (N = 41), UK (N = 2), Iran (N = 4), Korea (N = 1), unknown (N = 1)
Era of Service^b^ | Not specified (N = 1), other (N = 2), peacetime (N = 2), Afghanistan War (OEF) (N = 3), Iran-Iraq War (N = 4), Iraq War (OIF, OND) (N = 5), Vietnam War (N = 7), Persian Gulf War (N = 29)
Exposure Categories^c^ | Chemical weapons (N = 17), multiple exposures/mixed exposures (N = 13), oil well fire (N = 11), pesticides (N = 8), herbicides (N = 8), burn pits (N = 7), Khamisiyah-related exposure (N = 6), JP-8 and/or diesel (N = 6), depleted uranium (N = 3), insecticides (N = 3), air pollutions (N = 2), Camp Lejeune (N = 1), Gulf War-related exposures (N = 1), chemicals not otherwise specified (N = 4), other exposures not otherwise specified (N = 11)
Outcome Categories^d^ | Neurocognitive (N = 22), psychiatric diagnoses (N = 19), psychiatric symptoms (N = 30)

Notes.

a Cohorts with and without control groups refer to whether the cohort included nontoxic exposed control groups as comparators for the toxic exposed group.

b Not mutually exclusive categories. Four studies reported more than 1 era of service.

c Not mutually exclusive categories. Fourteen studies reported more than 1 exposure category.

d Not mutually exclusive categories. Twenty-two studies reported more than 1 outcome category.

## KEY QUESTION 1 EVIDENCE MAPPING OF SYMPTOMS AND DIAGNOSES

### Psychiatric Symptoms and Diagnoses

In total, 45 of the 49 included studies assessed the relationship between psychiatric symptoms or diagnoses and military toxic exposures; most studies reported more than 1 association.

Of the unique symptom/diagnosis and military toxic exposure associations analyzed, 53.9% were examined in a Persian Gulf War Veteran sample (N = 123), with considerably fewer analyses conducted among Vietnam War (N = 38; 16.7%), Iran-Iraq War (N = 23; 10.1%), Operation Enduring Freedom (OEF), Operation Iraqi Freedom (OIF), Operation New Dawn (OND) (N = 21; 9.2%), and Bosnian War (N = 20; 8.8%) Veteran samples. Peacetime Veteran samples (N = 3; 1.3%) included the fewest analyses. Of the types of toxic exposures examined in the literature, the relationship between chemical weapons exposures and psychiatric outcomes was the most common (N = 54) and was predominantly examined among Persian Gulf War and Iran-Iraq War Veteran samples. Comparatively, the relationship between herbicide exposure and psychiatric outcomes was predominantly studied among Vietnam War Veterans. Relatively few tests were conducted to examine the relationship between exposure to burn pits (N = 13) or Camp Lejeune contaminated water (N = 3) and psychiatric outcomes.

Regarding psychiatric outcomes, the literature has primarily tested the relationship between toxic exposures and global/composite mental health outcomes (ie, other [multiple symptoms/diagnosis]; N = 49), depressive symptoms or diagnoses (N = 46), or posttraumatic stress symptoms or PTSD diagnoses (N = 40); a variety of toxic exposures were represented in these tests. A dearth of analyses has assessed the co-occurrence of military toxic exposures and substance use (N = 6) and suicidality (N = 1). Figure 1 depicts the number of associations between toxic exposure type and psychiatric outcomes analyzed (N = 228) as well as the service era of the sample in which these associations were tested.

Figure 1 Visualization of Associations Across Included Studies by Era of Service, Military Toxic Exposures, and Psychiatric Symptoms and Diagnosis

### Symptoms of Depression

#### Global Depressive Symptoms

We identified 17 studies that examined associations of depressive symptoms with various military environment exposures.^1,6,14,17–30^ In these studies, depressive symptoms were measured using a wide variety of self-report instruments including the Depression Clinical Scale of the Minnesota Multiphasic Personality Inventory (MMPI; N = 2 studies),^17,26^ the 8-item Patient Health Questionnaire (PHQ-8; N = 1),^19^ the Beck Depression Inventory for Primary Care (BDI-PC; N = 1)^21^ or BDI-II (N = 3),^21,25,28^ questions adapted from the Psychiatric Epidemiologic Research Interview (PERI; N = 1),^14^ Profile of Mood States-Depression (POMS; N = 1),^30^ PRIME-MD (N = 1),^24^ and a multi-item health checklist that included 1 question about depression (N =4).^1,22,23,29^ Finally, 3 studies did not report how depression was assessed.^6,20,27^ Depressive symptoms were mainly examined as a dichotomous (yes/no) variable. One study specified severity of depressive symptoms (moderate to severe) using the BDI-II.^28^ Another study assessed symptoms over time and calculated depressive symptom trajectories (none, symptom developed, mixed, remitting, and consistent).^22^ Six studies did not report the racial/ethnic makeup of participants. Of the studies that did report racial/ethnic composition of the sample, most consisted of male participants (more than 82%) and were White and non-Hispanic (range: 58.0%-98.2% across 11 studies).

Among these 17 studies, chemicals constituted the most-examined type of exposure, including chemical weapons (ie, sarin gas; N = 8),^1,6,20,25,27–29^ pesticides (N =3),^6,23,30^ herbicides (ie, Agent Orange; N = 3),^14,17,26^ and organophosphate esters (N = 1).^19^ Three studies examined exposures to air pollutants from oil well fires.^23,24,29^ One study characterized duration of exposure into categories of 1–5, 6–30, and more than 30 days.^24^ Three studies examined “other” exposures, specifically to JP-8 and/or diesel.^23^ Finally, 1 study examined mixed exposures during the Persian Gulf War and another from OEF and OIF.^18^ We did not identify any studies that examined exposures related to Camp Lejeune, heavy metals, or radiation.

Nine studies included Gulf War-era Veterans,^1,6,21–24,28–30^ 3 examined Vietnam-era U.S. Veterans,^14,17,26^ 3 were conducted among Iranian Veterans who served in the Iran-Iraq War,^20,25,27^ 1 included Veterans from OEF and OIF,^18^ and 1 study included aircraft maintenance worker Veterans of all eras.^19^

#### Crying Easily

We identified 2 studies that examined the association of crying easily^22,29^ with military exposures. The studies used 2 different self-report multi-item health questionnaires that assessed crying easily as a yes/no outcome. One study examined this longitudinally,^29^ analyzing symptom trajectories (none, symptom developed, mixed, remitting, and consistent). Both studies included multiple exposures experienced by Veterans of the Persian Gulf War era, such as self-reported exposure to chemical weapons, exposure to the Khamisiyah weapons depot sarin plume, and “other” exposures to tent heaters.^22,29^

### Depressive Disorders

We identified 5 studies that examined associations between depressive disorders and military toxic exposures.^15,24,31–33^ Three of these focused only on MDD,^24,32,33^ 1 explored “depressive disorders” not defined,^15^ and 1 explored both MDD and a broader category of depressive disorders (eg, bipolar disorder, dysthymia, other mood disorders).^31^ Only 1 study used diagnostic codes to define depressive disorders,^15^ while 2 used structured clinical interviews.^24,31^ One study relied on participant endorsement of MDD,^33^ and the last study did not report how MDD was assessed.^32^ Most studies reported the sex (N = 5) and racial composition (N = 4) of the sample,^1,15,24,31,32^ which were mostly male (93% or more) and non-Hispanic White (range: 65.0%-93.2%).

Among the 5 studies that explored a diagnosis of depression and military exposures,^1,15,24,31,32^ the most commonly studied exposure was to chemicals, including chemical weapons (N = 2) (ie, sulfur mustard; N = 1,^31^ sarin; N =1^33^), herbicides (N = 1) (ie, Agent Orange),^32^ and Camp Lejeune water contamination (N = 1).^15^ Last, 1 study assessed exposure to oil well fires in Kuwait.^24^ We did not identify any studies that examined pesticides, heavy metals, or radiation-related exposures. The identified studies included both U.S. Military Veterans (N = 4)^15,24,32,33^ and Iranian Military Veterans who served in the Iran-Iraq War (N = 1).^31^ Three of the studies included U.S. military Veterans: 2 from the Gulf War era,^24,33^ and 1 from the Vietnam era.^32^ Another study was of U.S. Veterans who lived at Camp Lejeune.^15^

### Symptoms of Anxiety

#### Global Symptoms of Anxiety

We identified 7 studies that examined associations between symptoms of anxiety and various military exposures.^1,14,20,21,25,26,29^ Each study used a separate measure to assess anxiety, including the Global Health Questionnaire-28 (GHQ-28),^20^ Beck Anxiety Inventory,^21^ the Zung Self-Rating Anxiety Scale,^25^ the MMPI-II Phobias Scale,^26^ a 4-item health checklist,^29^ 1 item assessing anxiety on a broader health questionnaire,^1^ and 1 question adapted from the Psychiatric Epidemiologic Research Interview (PERI; N =1^14^).

The preponderance (N = 6) of studies assessing symptoms of anxiety examined chemical exposures in the following categories: pesticides (ie, Agent Orange; N = 2)^14,26^ and chemical weapons (ie, sulfur mustard gas, sarin, Khamisiyah munitions depot explosion; N = 4).^1,20,25,29^ The seventh study examined exposure to tent heater exhaust.^21^ We did not identify any studies that examined anxiety in the context of exposure to airborne hazards, Camp Lejeune contaminated water, radiation, or heavy metals. Regarding era of military service, 3 studies were focused on Veterans from the Persian Gulf era,^1,21,29^ 2 included Vietnam era Veterans,^14,26^ and 2 included Iraqi Veterans from the Iraq-Iran war.^20,25^ Of the 5 studies^14,20,21,25,29^ that reported sociodemographic characteristics on their full sample, studies consisted of mostly White (range: 82.2%-95%) and male (range: 76%-100%) participants,^14,20,25^ with a mean age that ranged from 30.2 to 42.0 years. Notably, King et al included 24% female and 5% Hispanic participants.^21^

#### Feeling Nervous or Tense

Two studies^22,30^ examined feeling nervous or tense. One assessed this using the POMS Tension subscale, while the other used a single item off a multi-item health questionnaire that was repeated over time, ultimately resulting in 5 symptom trajectories (none, symptom develops, mixed, remitting, and consistent). Chemicals were the predominant military exposure, including potential exposure to the Khamisiyah munitions depot explosion^22^ and exposure to pesticides.^30^ One of the studies also included exposure to tent heaters.^22^ Both studies were focused on Veterans of the Persian Gulf War era of mixed military branches. Only 1 study reported sociodemographic data for the entire cohort, which was predominantly male (87.4%) and White (92.8%), with a mean age of 32.3 years.^22^

### Anxiety Disorders

The association of anxiety disorders and military exposures was explored in 3 studies and across 4 unique associations.^22,31,33^ Obsessive-compulsive disorder was the outcome of interest in 2 studies that used different assessment methods (ie, structured clinical interview,^31^ self-report^33^). One study assessed the presence of any anxiety disorder via diagnostic codes,^15^ and the last explored a diagnosis of hypochondriasis via structured clinical interview.^31^ All the studies were of associations with military-related chemical exposure, with the most common being chemical weapons (N = 2; sulfur mustard gas,^31^ sarin nerve agent^33^). The last study examined toxic water at Camp Lejeune.^15^ Two studies reported racial/ethnic composition of the study samples and consisted of mostly White, non-Hispanic individuals (range: 66%-69%).^15,31^ Three studies reported sex, which was overwhelmingly male (95% or more).^15,31,33^ Two studies were with U.S. Veterans (Gulf War era,^33^ military personnel who lived at Camp Lejeune,^15^ and Iranian Veterans from the Iran-Iraq War.^31^

### Symptoms of PTSD

We identified 9 studies that included symptoms of PTSD as an outcome,^1,17,21,25,34–38^ with 24 different exposures. In most of these studies (N = 8), PTSD symptoms were examined using various multi-item, self-report measures, including a 15- and 17-item PTSD symptom checklist derived from the Diagnostic and Statistical Manual of Mental Disorders (DSM),^1,34^ the PTSD scale on the MMPI first version,^17^ the General Health Questionnaire (GHQ)-12 Stress Syndrome subscale,^35^ and the PTSD Checklist-Military version. One study used the Clinician-Administered PTSD Scale to determine PTSD symptom severity.^36^ A wide range of exposures were examined in this body of literature, with most exposures in the chemicals category. Specifically, 2 studies examined exposure to different levels of herbicides.^17,34^ Another 3 studies examined exposure to pesticides;^35,37,38^ 4 studies fell into the chemical weapons subcategory;^1,25,37,38^ and 1 final study included other various chemicals such as solvents and paints.^35^ In the air pollution category, 2 studies examined exposure to burn pits,^35,37^ and 1 also included exposure to oil well fires and exhaust from heaters and generators.^37^ One study examined the association with radiation (depleted uranium).^35^ Two studies included exposure to multiple Gulf War-related exposures,^36,37^ and another included multiple exposures during the Bosnia era.^35^ A final study included exposure to tent heaters or diesel fuel.^21,35,37,38^ We did not identify any studies that examined Camp Lejeune-related exposures or exposures to heavy metals.

Most of these studies (N = 5) were conducted among Veterans of the Gulf War Era. Of the remaining 4, 2 studies examining herbicides were conducted among Vietnam-era Veterans,^17,34^ 1 included UK Veterans from the Bosnia era,^35^ and 1 study included Iranian Veterans from the Iran-Iraq war.^25^ Across the studies that reported sociodemographic characteristics, the sample was predominately male (range: 75.1%-100%) and White with unspecified ethnicity (72.1%-98.6%). Of note, 2 studies had a slightly higher composition of female Veterans (~25%),^1,21^ and 1 study included a relatively higher proportion of individuals who identified as Black (21.5%).^1^ Several studies reported average age of the sample, which ranged from 30.9 to 42.0 years old, though some studies presented ranges spanning younger than 24 years to older than 40 years.

### Posttraumatic Stress Disorder

We identified 6 studies that assessed the association between diagnosis of PTSD and military exposures.^20,27,31–33,39^ Half the studies used a structured clinical interview to identify military Veterans with PTSD.^20,27,31^ Two studies used self-reports,^33,39^ and 1 did not report how PTSD was assessed.^32^ Five studies explored chemical weapons exposures (N = 3, sulfur mustard gas^20,27,31^; N = 2, sarin nerve agent^27,33^). One included self-reported exposure to biological or chemical warfare agents.^39^ The last study explored exposure to the herbicide Agent Orange.^32^ These studies were conducted with U.S. miliary personnel from the Vietnam era (N = 1),^32^ the Gulf War (N = 1),^33^ or a combination of personnel from the Gulf War or Bosnia era (N = 1).^39^ The other 3 studies were conducted with Iranian military Veterans from the Iran-Iraq War and were conducted with exclusively male samples (N =3).^20,27,31^ Among the 3 U.S. military studies, participants were mostly non-Hispanic White (range: 66%-78%) and male (73%- 98%).^32,33,39^

### Sleep Dysfunction

#### Sleep Problems

We identified 7 studies that included associations between difficulty sleeping and various military exposures.^1,6,18,22,23,28,29^ Within this category, all studies assessed constructs such as “trouble sleeping,” “sleep problems,” “difficulty sleeping,” or “sleepiness during the day” using 1 or 2 yes/no items on a multi-item health questionnaire. One study was repeated over time, resulting in 5 symptom trajectories of trouble sleeping (none, symptoms develop, mixed, remitting, and consistent).^22^

The most common military exposure explored in these unique associations was chemicals, specifically potential exposure to chemical weapons (N = 4),^1,6,22,28,29^ proximity to the Khamisiyah munitions depot detonation (N = 2),^22,29^ or pesticides (N = 2).^6,23^ One study examined exposure to air pollution from oil well fires.^23^ Many of these associations also explored other exposures not categorized as chemicals or air pollution, or explored multiple exposures, including exposures to tent heaters^22,23,29^; a combination of nuclear, biological, or chemical exposures^18^; and exposure to fuel such as diesel.^23^

Most studies (N = 6) included Gulf War-era service members from mixed branches, the majority of which were Army. The remaining study included OIF/OEF-era service members.^18^ Among the studies that reported sociodemographic characteristics, the mean or median reported age ranged from 29 to 49 years old and the majority were male (range: 66.1%-91.6%). Reported race for 4 studies was largely White with unspecified ethnicity (range: 82.2 %-92.8%), while 2 studies included a higher proportion of individuals identifying as Black (32%^23^ and 33.5%^18^). One study did not report sociodemographic data.^28^

#### Sleep Disorders

Two studies looked at sleep disorders in relationship to chemical exposures. One study assessed “sleep disorders” among Vietnam-era Veterans exposed to Agent Orange.^32^ The other study assessed rapid eye movement sleep behavior disorder and Veterans exposed to contaminated water at Camp Lejeune.^15^ In the Camp Lejeune study, ICD-9 and ICD-10 codes were used to identify the sleep disorder and military service records were used to approximate exposure status. In the Agent Orange study, chemical exposure and sleep disorder were assessed via Veteran self-report. Both studies were majority White (range: 69%-78%) and male (95% or more).

### Psychotic Disorders and Related Symptoms

#### Symptoms of Psychosis

We identified 3 studies that examined symptoms of psychosis, including hallucinations,^17,31^ schizophrenia,^26^ and psychotic delusions.^17^ Outcomes were examined using clinical scales on the MMPI-schizophrenia scale,^17^ the Millon Clinical Multiaxial Inventory (MCMI)-psychotic delusions scale,^17^ and using DSM-III criteria.^31^ All exposures examined were chemicals: 1 examined exposure to sulfur mustard gas and the other 2 examined exposure to herbicide dioxin (found in Agent Orange). The 2 studies on Agent Orange focused on Vietnam-era Veterans and the study on sulfur mustard gas was on Iraqi Veterans from the Iran-Iraq War.^17,26^ Studies included 100% men with a mean age range of 45.2 to 53.2 years and did not report race or ethnicity.^17,26,31^

#### Schizophrenia or Psychotic Disorders

Two studies reported schizophrenia or psychotic disorders.^31,40^ One study assessed the relationship between self-reported schizophrenia or other psychotic disorders and Agent Orange among Korean Veterans from the Vietnam War.^40^ Agent Orange was assessed via self-report and military service records. One study evaluated sulfur mustard gas and psychotic disorders via structured clinical interview with Iranian military Veterans from the Iran-Iraq War.^31^ Sulfur mustard gas exposure was obtained through the sulfur mustard gas survivor database. Mean age was reported as 58.8 years among the Korean Veterans group and 45.2 years among the 100% male Iranian Veteran group. Race was not reported in either of these studies.

#### Suicidality or Nonsuicidal Self-Injury

We identified only 1 large cohort study^41^ (N = 598,269) that examined the association between death by suicide and exposure to the Khamisiyah munitions depot explosion (chemical weapons) among Veterans of the Persian Gulf War using all-cause mortality data from U.S. Department of Defense service records.^41^ The cohort was 93% male and 70.2% identified as White.

### Substance Use and Substance Use Disorders

#### Substance Use

Three studies included outcomes related to substance use and military exposures. Studies used different self-report questionnaires (the 1992 version of the MCMI-substance abuse scale,^17^ Chemical Use Inventory,^26^ measures that inquired about various illicit substances [eg, cannabis, methamphetamines, barbiturates, heroin^34^]). All examined exposure to the chemical herbicide Agent Orange and all were conducted among Vietnam-era Veterans from different branches of service in the U.S. military. Only 1 study reported sociodemographic characteristics of the sample and 100% were male; race for the overall sample was not reported.

#### Substance Use Disorders

We identified 3 other studies^31–33^ that examined the association of substance use disorders (SUDs) with military environment exposures.^31–33^ One study assessed SUDs via self-report of historical diagnoses,^33^ another used a structured clinical interview,^31^ and the third study extracted diagnostic codes from medical records.^32^ All 3 studies looked at the relationship between SUDs and chemical exposures on overseas deployments. Two looked specifically at exposure to chemical weapons via a pre-existing record of exposure (anticholinesterase agents and sulfur mustard)^31,33^ and 1 at self-reported exposure to an herbicide (Agent Orange).^32^ One study was of Iranian Veterans (non-U.S. military)^31^; the other 2 studies were U.S. military Veterans deployed to Vietnam^32^ or Khamisiyah, Iraq, during the Persian Gulf War.^33^ Two studies were conducted among all-male (mean age = 45.2 years)^31^ or nearly all male (98%, mean age = 62 years)^32^ participants. No other demographic information was reported in these studies. No identified studies looked at air pollution, heavy metals, radiation, or other toxic exposures.

### Other Psychiatric Symptoms and Diagnoses

#### Other Individual Psychiatric Symptoms

Seven studies examined other individual mental health symptoms that were not captured in the above categories.^14,17,18,26,28,30,42^ Of the individual symptoms, these can be further categorized into “other mood-related outcomes,” including hypomania,^17,26^ psychasthenia,^17,26^ mood swings,^28^ and other mood symptoms.^42^ A second, broader “other” category was comprised of anger or irritability (included in 5 studies),^1,14,18,28,30^ hostility,^26^ helplessness, hysteria, avoidant, antisocial, narcissistic paranoid, somatoform, dependent, schizoid, and paranoia.^17^ Most symptoms were captured using a subscale of the MMPI or MCMI and some were assessed using 1- or 2-item self-report surveys. Across the 7 studies that included individual symptoms, the most common exposure category was chemicals (herbicides [N = 3],^14,17,26^ pesticides [N = 1],^30^ chemical weapons [ie, sarin; N = 1]^28^). One study explored multiple exposures^18^ and 1 explored oil well air pollution (N = 1).^42^ Three included Vietnam-era Veterans^14,17,26^ and 3 included Persian Gulf War-era Veterans.^28,30,42^ Of the studies that reported sociodemographic characteristics, the reported age of the samples ranged from 33 to 55 years old, with the majority identifying as male (range: 66%-100%) and White (range: 72%-98.6%).

#### Composite Psychiatric Diagnoses

We identified 8 studies that assessed a composite of mental health diagnoses. One study looked at a number of mental health conditions (ie, any mood disorder, dipolar disorder, and somatoform disorder) in relation to sulfur mustard exposure.^31^ The remaining 7 studies assessed participants with any mental health (composite) diagnosis in relation to a number of different toxic exposures (oil fires,^43,44^ pesticides,^33,45,46^ chemical weapons,^47^ and Khamisiyah-related chemicals [20 different toxic exposures^48^]). No other studies in relation to any other exposure category were identified. The most common way that mental health diagnoses were determined was through review of medical records databases (N = 5)^43–46,48^ and 1 used a structured clinical interview.^31^ The demographic information of participants was not clearly reported for the majority of the composite mental health studies.^33,43–46,48^

#### Composite Symptoms Outcomes

Six studies^18,21,23,35,49,50^ examined the following composite mental health outcomes: depression and anxiety^23^; composite score on a general mental health scale, including the SF-12^21^ or GHQ-28^35^; or a broad psychological symptom (eg, inability to fall asleep, feeling depressed, anxiety, or nervousness). Moreover, composite GWI/CMI symptoms outcome was included in 6 studies^18,49–53^; because they included a mental health component, we included them in this evidence map. Among the studies that included composite outcomes, the exposures were burn pits (N = 1)^54^ or mixed/multiple exposures (N = 5). The majority (N = 5) of the studies focused on Persian Gulf War-era Veterans and the remaining 1 focused on OIF/OEF Veterans. Most of the samples identified as male (range: 66%-88%) and White (58.8% or greater), with ages ranging from 29 to 50 years.

### Neurocognitive Functioning

The relationship between toxic exposures and neurocognitive functioning was assessed by 22 studies.^1,6,15,18,22,23,26,28–32,44,49,50,54–61^ To assess neurocognitive status, 15 of these studies relied on subjective (self-report) data,^1,6,18,22,23,28,29,49,50,54,56–58,60,61^ and 5 studies used objective data (mental status examination^31^ and standardized test battery^26,30,55,59^). Two studies used a clinically established neurodegenerative diagnosis.^15,32^ Demographic data were incomplete or not reported for most of these studies. Of the studies that did report demographic information, participants were mostly White and male.^15,26,30,32^

Most studies reported a test of more than 1 association. Of the associations analyzed, 57.0% were examined in OEF-OEF-OND Veteran samples (N = 90), while the remainder of the analyses were conducted among Persian Gulf War (N = 27; 17.1%), Vietnam War (N = 15; 9.5%), and Iran-Iraq War (N = 5; 3.2%), and peacetime Veteran samples (N = 1; 0.6%). Additionally, a considerable proportion of analyses were conducted among Veterans from unspecified service eras (N = 20; 12.7%). Of the types of toxic exposures examined in the current literature, the relationship between other exposure types not categorized elsewhere (eg, Scud missiles, anti-nerve gas pills) and neurocognitive functioning was the most frequently tested (N = 38) and was examined among OEF-OIF-OND, Persian Gulf War, and unspecified-era Veteran samples. Relatively few tests were conducted to examine the relationship between exposure to burn pits (N = 9) or Camp Lejeune contaminated water (N = 1) and neurocognitive outcomes. Regarding neurocognitive outcomes, the current literature has primarily tested the relationship between toxic exposures and other neurocognitive outcomes not captured elsewhere, including single-construct measures (N = 36), such as self-reported impaired cognition, and composite or multi-construct measures (N = 32), such as those used to assess symptoms associated with chronic multi-symptom illness and Parkinson’s disease. Few analyses were conducted to examine the relationship between toxic exposures and executive functioning (N = 13), as well as toxic exposures and any major neurocognitive disorder (N = 2). Figure 2 depicts the number of associations between toxic exposure type and neurocognitive outcomes analyzed in the current literature (N = 158), and the service era of the sample in which the associations were tested.

Figure 2 Visualization of Associations Across Included Studies by Era of Service, Military Toxic Exposures, and Neurocognitive Symptoms and Diagnosis

Only 9 of the 22 studies analyzed neurocognition as an independent construct (not combined with other psychological or physical symptoms/diagnoses).^15,26,30–32,44,49,55,57,59^ Of the 9 studies, 2 focused on the relationship between toxic exposure and a neurocognitive diagnosis.^15,32^ Both neurocognitive diagnosis studies assessed major neurocognitive disorders (dementia): 1 in relation to contaminated water in Camp Lejeune^15^ and the other in a cohort of Vietnam-era Veterans exposed to Agent Orange.^32^ One of the studies assessed an “impaired cognition syndrome,” which was not defined. Six studies assessed neurocognitive symptoms in relation to chemical exposures.^26,30,31,49,55,59^ Neurocognitive symptoms were assessed in relation to Agent Orange exposure in Vietnam^26,55^ and sulfur mustard gas in Iraq war Veterans.^31^ Gulf War Veterans who had mixed exposures (poison gas or germ warfare, [N = 1];^49^ Khamisiyah-related, [N = 1]^59^), exposure to pesticides, or had other exposures (anti-nerve gas pills) were also assessed for neurocognitive symptoms.^30,59^ Toxic exposures were assessed based on self-reports,^26,30,49^ existing records,^31,32^ and blood draws,^55^ as well as geographical proximity estimates.^15,59^

The remaining 13 studies analyzed subjective cognitive complaints (eg, memory or concentration) as part of a combined multi-system physiological-psychological construct. This included 11 Gulf War exposure studies,^1,6,22,23,28,29,50,56,58,60,61^ 1 Iraq burn pit exposure study,^54^ and 1 Iraq-Afghanistan study with a composite toxic exposure variable.^18^ The majority of these studies used the Centers for Disease Control and Prevention definition of chronic multi-symptom illness (CMI). One of these studies did not look at CMI specifically, but rather non-motor symptoms of Parkinson’s disease.^56^ Military toxic exposures were assessed using subjective data, with the most common being self-report (N = 9).^6,22,23,29,50,56,58,60,61^ Specific Gulf war exposures included chemicals,^6,50^ burn pits,^31^ oil fires,^29^ mixed exposures,^58,60,61^ Khamisiyah-related,^1,22,28,29,56^ and other exposures related to Scud missiles^50^ or JP-8 fuels.^22,23,29^

## KEY QUESTION 2 EVIDENCE MAPPING OF PREVALENCE, INCIDENCE, AND ASSOCIATION

In total, 41 of the included 49 studies provided information about the association between military toxic exposures and psychiatric symptoms and diagnosis or neurocognitive function. The other 8 studies reported composite outcomes of psychiatric symptoms or physical symptoms but did not provide separate analyses by neurocognitive or psychiatric outcomes (eg, neurocognitive and mood symptoms). Figure 3 provides a visualization of the patterns in associations across psychiatric outcomes. In some instances, studies only reported no significant association or a significant association without reporting the strength of these associations. We note these patterns as well. For the figures below, we selected 1 unique association per outcome and exposure type for each study. Thus, 1 study could contribute more than 1 association if multiple pairs of outcomes and exposures were explored in the study. The methods section details our process of selecting these unique associations.

Figure 3 Size of Associations Across Most Common Exposures and Most Common Symptoms and Conditions

Notes. This figure provides a visualization of the number of associations across studies cateogrized into effect sizes within outcome category, separated by 4 major groups of toxic exposures. Bubble size is an indication of relative number of measured associations reported in the included studies. The chemical category includes chemical exposures, chemical weapons, JP-8 and other diesel, pesticides, and herbicides.

For psychiatric disorders and symptoms, depression was the most assessed outcome with military toxic exposures, followed by PTSD and anxiety (Figure 4). Exposure to chemicals was the most reported exposure in relation to psychiatric concerns and few assessed exposure to radiation or heavy metals. While a total of 22 studies addressed the relationship between toxic exposures and neurocognitive functioning, only 9 of these studies assessed neurocognitive functioning as an independent construct. Like psychiatric outcomes, the most common military exposure in these studies was chemicals. When mapping the strength of associations across psychiatric outcomes, large associations were most frequent among studies of chemical exposures and symptoms and diagnosis of PTSD, followed by symptoms or diagnoses of depression and anxiety. For neurocognitive symptoms and diagnoses, the most common effect estimates were those that only reported a nonsignificant p value. Next, we detail the pattern of associations across more discrete categories of military exposures and psychiatric concerns.

### Depression

#### Symptoms of Depression

There were 17 studies that included depressive symptoms as an outcome and explored associations with toxic exposures during military service. A range of exposures were assessed, with the majority focusing on some type of chemical exposure (eg, chemical weapons, herbicides, and/or pesticides) as well as different levels of depression (eg, mild or severe cases; different types of symptom trajectories including none, symptom developed, mixed, remitting, and consistent). We did not identify any studies that examined radiation, heavy metals, or Camp Lejeune-related chemical exposures. Within and across exposure categories, findings were mixed, limiting our ability to comment on patterns in these diverse military exposures.

The most examined type of exposure was to chemicals, including potential exposure to chemical weapons (N = 8),^1,6,20,22,25,27–29^ pesticides (N = 3),^6,23,30^, herbicides (ie, Agent Orange; N = 3^14,17,26^) and other chemicals such as organophosphate esters.^19^ Among chemical weapons, the specific exposures included sulfur mustard gas,^20^ potential exposure to chemical weapons alert,^6,22^ and potential exposure to sarin gas (based in some studies on being in range of the Khamisiyah weapons depot detonation).^22,29^ Across these chemical weapon exposures, the strength of association with the presence of depressive symptoms or a particular type of depression symptom trajectory ranged from none to large.^22,27^ Three studies did not report sufficient data to determine an effect size.^20,25,28^ Among the studies that assessed pesticides, 1 reported a large effect of association but did not specify the route of exposure to the pesticide.^30^ One included a combination pesticide variable (ie, insecticides, pesticides, flea collars) and did not identify an association.^6^ The third study did not contain sufficient data to estimate an effect size.^23^ Three studies examined herbicides and depression, with a range from no association to large association.^14,17,26^ A final study assessed chemical exposure to organophosphate esters among airplane maintenance workers via 3 routes of exposure: ingestion, inhalation, and skin contact. It reported a large effect with the first 2 routes and a moderate effect with skin.^19^

Four studies examined exposures to JP-8 and/or diesel^19,23^ and tent heaters.^22,29^ Across the JP-8 and/or diesel studies, 1 reported a large association^19^ and the other did not have sufficient information to assess effect size.^23^ Tent heater exposure was assessed with the presence or absence of depression or with different trajectories of depressive symptoms in 2 studies; 1 did not find an association and the other found a range of none to small for different trajectories of depressive symptoms.^22^

Several additional studies examined multiple exposures. The first examined depression symptoms with a composite toxic exposure score from the DRRI and did not find an association.^21^ Another study examined a mix of exposures from the Persian Gulf War^23^; this study did not find any association between individual exposures and endorsement of depressive symptoms. A final study examined mixed exposures during OEF and OIF and looked at a combined outcome of depression or anxiety and did not report an association.^18^ Three studies examined exposure to air pollution, burn pits, or fumes, all of which specifically looked at exposure to oil well fires.^23,24,29^ Of those that were reported, the strengths of association across these ranged from none to large, with the most common association being moderate strength. Overall, there was a trend that the strength of association increased as the frequency of exposure increased.^24^ The third study did not report findings.^23^

#### Crying Easily

Across the 2 studies included, odds ratios were used to examine the association between crying easily (as a dichotomous yes/no variable) and trajectories of crying easily (none, symptoms develop, mixed, remitting, and consistent) with 2 categories of military exposures (chemical [chemical weapons] and other [tent heaters]). Within the chemical exposures, 4 separate analyses looked at exposure to Khamisiyah plume sarin exposure and different trajectories of crying easily; 1 found a moderate association^29^ with exposure to the Khamisiyah plume and 3 did not find an association.^22^ Several other analyses across these 2 studies examined exposure to tent heater exhaust and found large effects to small effects with the likelihood of different trajectories of crying easily.^22,29^ Namely, exposure to tent heaters was most strongly associated with the consistent presence of the crying easily symptom.

#### Depressive Disorders

Five studies explored a diagnosis of a depressive disorder and military toxic exposures,^15,24,31–33^ including chemical weapons (N = 2) (ie, sulfur mustard gas [N = 1^31^], sarin [N = 1^33^]), herbicides (ie, Agent Orange [N = 1^32^]), and Camp Lejeune water contamination (N = 1^15^). Last, 1 study assessed exposure to oil well fires in Kuwait.^24^ None of the studies characterized duration of exposures. Across all the unique associations in these 5 studies, all but 1 reported no association between some type of depressive disorder and military-related chemical exposures.

Figure 4 depicts the number of associations between toxic exposure type and depressive symptoms/diagnoses analyzed in the current literature and the reported effect sizes of each relationship analyzed, categorized by toxic exposure type. Across exposure types, effect sizes were highly heterogeneous. Most analyses examined the relationship between toxic exposure and depressive symptoms/diagnoses focused on chemical weapons exposure; outcomes were most frequently not reported or no association was observed. The relationship between burn pits, depleted uranium, or air pollutants not related to oil well fires and depressive outcomes has not been examined.

Figure 4 Association Sizes for Depression and Depression Symptoms Across Exposures

Notes. Significance is only reported for those studies that did not report a summary estimate. Otherwise, significance is not incorporated into the overall effect size categories.

### Anxiety

#### Global Symptoms of Anxiety

We identified a total of 7 studies that assessed the association of military exposures and symptoms of anxiety; all assessed global symptoms of anxiety. The anxiety symptoms literature suggests that Agent Orange exposure may be associated with the endorsement of global symptoms of anxiety. Exposure to other chemicals, including sarin, as well as other exposures such as tent heaters, was mixed. Overall, there was generally insufficient information to draw clear conclusion about overall patterns in the strengths of these associations. However, herbicides and pesticides do appear to be more consistently associated with the presence of anxiety symptoms relative to other kinds of exposures.

Most of the studies that assessed global anxiety symptoms investigated exposure to various chemicals. Within the subcategories of chemicals, 3 analyses across 2 studies examined exposure to the herbicide Agent Orange.^14,26^ Two reported a large effect size and 1 reported a small effect of the associations between Agent Orange and anxiety symptoms.^14,26^ Exposure to chemical munitions broadly, and those specifically containing sarin and cyclosarin, was identified in 4 studies; 2 of which reported no association between chemical munitions exposures and endorsement of symptoms of anxiety,^1,29^ and 2 of which did not have sufficient data to determine an effect size.^20,25^ One moderate strength association was found between self-reported count of multiple exposures (including biological, chemical, and radioactive exposures).^21^ Finally, exposure to tent heater exhaust was found to not be associated with endorsement of anxiety symptoms.^21^

#### Feelings of Nervousness and Tension

Two studies examined 12 unique associations of nervousness and tension, which were included as a continuous outcome on a validated muti-item measure or a trajectory (none, symptoms develops, mixed, remitting, and consistent) of repeated measures on a single item over time. Overall, there was no clear pattern of association. The majority of associations were examined with chemicals, including potential exposure to chemical munitions,^22^ the Khamisiyah munitions explosion, and pesticides^30^ as well as 4 analyses focused on “other” exposures such as tent heaters.^22^ Associations with exposure to chemical weapons and trajectories of nervousness and tension ranged from none to small, with the most commonly reported effect size as small. Within the analyses that examined the Khamisiyah munitions explosion, effect size ranged from no effect to small effect on trajectories of nervousness and tension, with the most common finding being no association.^22^ The same study looked at the association of exposure to tent heaters and different trajectories of feeling nervous or tense, and reported effect sizes ranging from none to large for each of the 4 trajectories, with the most common being moderate.^22^ The final study examined the self-reported endorsement of tension with exposure to pesticides and found a large strength of association.^30^

#### Anxiety Disorders

We identified a total of 3 studies that assessed associations of anxiety with military-related exposures to chemical weapons (N = 2^31,33^) or contaminated water at Camp Lejeune (N = 1^15^). The Camp Lejeune study reported no association between exposure to contaminated water and anxiety disorders.^15^ The 2 studies of chemical warfare agents reported mixed results. One study of Iranian military Veterans from the Iran-Iraq War reported no association between sulfur mustard gas and hypochondriasis or obsessive compulsive disorder.^31^ Another study of Gulf War Veterans and exposures to sarin nerve agents reported a moderate strength of association.^33^

Figure 5 depicts the number of associations between toxic exposure type and anxiety symptoms or disorders analyzed in the current literature, and the reported effect sizes of each relationship analyzed, categorized by toxic exposure type. Most analyses examining the relationship between toxic exposure and anxiety-related outcomes focused on chemical weapons exposure. Moreover, consistent with depressive outcome analyses, results of analyses examining the relationship between chemical weapons exposure and anxiety-related outcomes were most frequently not reported or no association was observed. Effect sizes were highly heterogeneous. The relationship between anxiety outcomes and several exposure types, including JP-8/jet fuel, oil well fires, Gulf War-related exposures, burn pits, depleted uranium, and other air pollutants have not been examined, suggesting multiple gaps in the literature.

Figure 5 Association Sizes for Anxiety and Anxiety Symptoms Across Exposures

Notes. Significance is only reported for those studies that did not report a summary estimate. Otherwise, significance is not incorporated into the overall effect size categories.

### PTSD and Related Symptoms

#### PTSD Symptoms

Nine studies examined PTSD symptoms in relation to 24 types of military exposures, several of which captured different routes of exposure.^35,37,38^ Across these studies, PTSD symptoms were consistently measured using a multi-item, self-report questionnaire, with the exception of 1 study that used a more rigorous clinician-administered tool.^36^ Only 1 study categorized PTSD symptoms into “low” and “high”^38^; the remaining 8 included the PTSD total score as a continuous or dichotomous variable.^1,17,21,25,34–37^ The most common exposure category was to chemicals, including herbicides (N = 2),^17,34^ pesticides (N = 3),^35,37,38^ and chemical weapons (N = 4).^1,25,37,38^ One study also included other chemicals such as solvents and paints.^35^ The overall pattern across these studies suggests PTSD most commonly had a large or moderate strength of association with the various examined chemicals or an association was not reported.

Across the 2 herbicide studies,^17,34^ the strength of associations ranged from no association to large association. Of note, the strongest associations were in a study of Agent Orange that reported large associations with both low and moderate levels of exposure (compared to those unexposed).^34^

Of the 3 studies that assessed pesticides, dermal exposure was consistently associated with moderate to large strength of association. In comparison, reporting exposure to the smell of pesticides had mixed results (range: no to large associations). Specifically, 1 study categorized exposures into “personal pesticides” and “pesticides on clothing” both of which had moderate strength of association with the endorsement of PTSD symptoms^35^ Another study that examined pesticides on clothing found a large association.^37^A final study included the smell of pesticides, and in 2 separate analyses found a range of none to large association with high PTSD symptoms.^38^

In the 4 studies that included chemical weapons, findings were mixed; 2 studies found a large effect^37,38^ and 2 studies did not report an effect.^1,25^ A final study including other chemical exposures such as solvents and paints found a large association between these chemicals and symptoms of post-traumatic stress.^35^

Four studies assessed exposure to air pollutants, radiation, or Gulf War-related mixed exposures. In the air pollution category, 2 studies examined exposure; the overall pattern of associations suggest an association between military-related air pollutant exposures and PTSD symptoms with a range from moderate to large. Two studies assessed burn pits^35,37^; 1 found a strong association^35^ and the other found a moderate association.^37^ The same study examined exposure to smoke from oil well fires and found a large association.^37^

We identified 1 radiation exposure study of depleted uranium that found a small strength of association.^35^ Two studies included exposure to multiple exposures^36,37^ and the overall pattern showed an association between this exposure and likelihood of PTSD symptoms. One study reported a large strength of association^37^ and another did not report sufficient data to calculate an effect size, but those in the exposure group had significantly higher PTSD symptoms compared to those in the unexposed group.

A final group of studies^21,35,37,38^ included exposures that fell into the “other” category, including exposure to tent heaters or diesel fuel^21,35,37,38^ via inhalation or skin contact, eating contaminated food, drinking contaminated water,^35,38^ and being within 1 mile of a Scud missile explosion.^21^ Most of these individual exposures were only examined in 1 association, limiting our ability to comment on patterns across studies. Two separate studies did include exposure to diesel (fumes and on the skin) and tent heaters.^35,38^ Across this range of exposures, the strength of associations were mixed, ranging from none to large.

#### Diagnosis of Posttraumatic Stress Disorder

We identified 6 studies that assessed PTSD diagnosis; all explored associations related to chemical exposures.^20,27,31–33,39^ The most common exposures studied were chemical weapons (sulfur mustard gas [N = 3],^20,27,31^ sarin nerve agent [N = 2]).^27,33^ Of these 4 studies, 1 did not report a comparative effect estimate between those exposed and unexposed to sulfur mustard gas,^20^ and the other 2 studies reported no association between either sulfur mustard gas^31^ or sarin.^33^ The fourth study assessed exposure to sulfur mustard gas and sarin—verified by military records among Iranian military Veterans of the Iran-Iraq War—and reported a large association.^27^ Another study assessed 3 self-reported exposures to chemical/biological warfare or countermeasures for these weapons: chemical/biological warfare agents, other medical countermeasures for chemical/biological warfare agent exposure, or alarms necessitating wearing chemical/biological warfare protective gear.^39^ The strength of associations ranged from small to large across all exposure categories, with the most common strength of association being large (4 of 6 associations). The last study that included a PTSD diagnosis as an outcome explored exposures to Agent Orange amoung Vietnam-era Veterans and reported a significant association with no reported strength of this association.^32^

Figure 6 depicts the number of associations between toxic exposure type and PTSD analyzed in the current literature and the reported effect sizes of each relationship analyzed categorized by toxic exposure type. Most analyses examining the relationship between toxic exposure and PTS symptoms and disorders focused on chemical weapons exposure; more than half of these analyses found large effects. Similarly, across pesticides, JP-8/jet fuel, other chemicals, burn pits, other air pollutants, multiple/mixed exposures, and other exposure types not categorized elsewhere, at least half of the analyses found large or medium effects on the relationship between toxic exposure and PTSD symptoms/disorder diagnoses. Importantly, the associations between Khamisiyah-related exposures and PTSD outcomes and Camp Lejeune contaminated water exposure and PTSD outcomes have not been explored. In sum, across PTSD analyses, large and moderate associations were frequently observed among a wide range of toxic exposure types, although notable gaps remain for Khamisiyah-related and Camp Lejeune contaminated water exposures.

Figure 6 Association Sizes for PTSD and Related Symptoms Across Exposures

Notes. Significance is only reported for those studies that did not report a summary estimate. Otherwise, significance is not incorporated into the overall effect size categories.

### Sleep Dysfunction Symptoms and Disorders

#### Sleep Dysfunction Symptoms

Sleep dysfunction symptoms were assessed in 7 studies. The preponderance of studies assessed the association of sleep disturbance symptoms and a military chemical exposure. Among these, the overall pattern suggests that there is little supporting evidence of an association between sleep dysfunction and these types of exposures. Among the chemical exposures examined, chemical weapons or potential exposure to the Khamisiyah munitions depot explosion were examined in 5 of the studies.^1,6,22,28,29^ Among these, there was a range of effect sizes found from large association^6^ to no association,^1,22^ with the most common being no association. One study examining difficulty sleeping and exposure to chemical weapons did not include sufficient information to determine an effect of association.^28^ Exposure to pesticides was examined in 2 studies.^6,23^ The first found that 34% of those who were exposed to pesticides self-reported sleep issues but contained insufficient data to comment of the effect size of that association.^23^ The second found a large effect size between exposure to pesticides and endorsement of sleep difficulties.^6^

Additional analyses in 4 studies^18,22,23,29^ explored other types of military-related exposures such as exposure to oil well fire air pollutants, tent heaters, or Gulf War-related multiple exposures and found little evidence to support strong associations between these military exposures and sleep disturbance symptoms. Two studies examined association with exposure to oil well fires among Veterans of the Persian Gulf War; 1 did not find an association^29^ and the other did not contain sufficient information to estimate an effect size.^23^ Exposure to tent heaters was examined in association with trajectories of sleeping difficulties in 1 study that found a range of association effect sizes from none to small, the most common of which was none.^22^ Another study did not find an effect between self-reported hypersomnolence or trouble sleeping and did not detect an effect.^29^ The remaining 2 studies included mixed or multiple exposures; 1 study looked at a range of exposure to various things from the Gulf War era (ie, tent heaters, chemical agent resistant coating paint, solvents/ petrochemicals) and did not contain sufficient data to determine an effect size for any individual exposure and the endorsement of sleep disturbance.^23^ The final study examined multiple exposures (biological, chemicals, and nuclear) with sleep disturbance symptoms and also did not contain sufficient data to estimate an effect size.^18^

#### Sleep Disorders

Sleep disorders and military exposures were explored in 2 additional studies as assessed by medical records review. Sleep disorders were not significantly associated with chemical exposure at Camp Lejeune^15^ but were significantly associated with Agent Orange exposure in Vietnam (no reported effect size).^32^

### Psychotic Disorders and Related Symptoms

We identified 3 studies that included symptoms of psychosis, including hallucinations, delusions, and symptoms of schizophrenia,^17,26,31^ and 2 additional studies of schizophrenia or psychotic disorders.^31,40^ These studies explored chemical exposures related to Agent Orange (N = 3) and sulfur mustard gas (N = 1). Across this small body of literature, the overall pattern suggests a moderate to strong strength of association between military-related Agent Orange exposures and psychotic disorders and psychosis symptoms. In the 2 studies on Agent Orange, a moderate effect of association was found with psychotic delusions^17^ and a large effect was found with symptoms of schizophrenia.^26^ Among those exposures to sulfur mustard gas, 2.9% had hallucinations,^31^ but effect size could not be determined. Yet self-reported schizophrenia or psychotic disorders were significantly associated with high levels of Agent Orange exposure in the 1 identified study (large effect size).^40^ One study of sulfur mustard gas reported no associations with schizophrenia or psychotic disorders among Iranian military Veterans.^31^

### Suicidality or Nonsuicidal Self-Injury

We only identified 1 large cohort study (N = 598,269) that examined the association between death by suicide and exposure to the Khamisiyah munitions depot explosion among Veterans of the Persian Gulf War using all-cause mortality data from Department of Defense service records.^41^ This study did not find an association between either 1 day of possible exposure or no reported exposure and rates of death by suicide; no studies of self-injurious behaviors were identified.

### Substance Use and Substance Use Disorders

#### Substance Use

Three studies included outcomes related to substance use and military exposures.^17,26,34^ All examined exposure to the chemical herbicide Agent Orange and used self-report measures that capture outcomes related to alcohol use and/or use of various illicit substances (eg, cannabis, methamphetamines, barbiturates, heroin). Among these studies, 1 study found a range of small to large strength of association with different levels of Agent Orange exposure (high, moderate, low),^34^ while the 2 others did not report sufficient data to estimate strength of association.

#### Substance Use Disorders

Three studies examined the association of SUDs with military environment exposures. Two studies found significant differences between SUDs and toxic exposures,^32–34^ though only 1 noted the strength of the effect (ie, large effect).^33^ No other common theme arose with regards to the pattern of exposure or strengths of association. All 3 studies looked at the relationship between SUDs and chemical exposures during military deployment. Two looked specifically at exposure to chemical weapons based on pre-existing records (eg, military service records) of exposure (anticholinesterase agents and sulfur mustard)^21,32^ and 1 at self-reported exposure to an herbicide (Agent Orange).^31^ One study was of Iranian Veterans^31^ and the other 2 studies were of U.S. military Veterans deployed to Vietnam^32^ or Khamisiyah, Iraq, during the Persian Gulf War.^33^

### Other Mental Health Symptoms and Conditions

We also identified 7 studies^14,17,18,26,28,30,42^ that assessed other individual symptoms of mental health that were not captured in the above categories; 6 included composite mental health outcomes.^18,21,23,35,49,54^ Six studies explored the relationship between participants with any mental health diagnosis in relation to a number of different toxic exposures.^33,43–46,48^

#### Other Mental Health Symptoms

Seven studies examined other individual symptoms of mental health that were not captured in the above categories^14,17,18,26,28,30,42^; 6 studies included composite mental health outcomes or reported a global chronic multi-symptom illness (CMI) or a GWI aggregated symptom score.^18,21,23,35,49,54^

For individual mental health outcomes, these symptoms were most often derived from examination of individual subscales of the MMPI or MCMI across 2 studies.^17,26^ The remainder were often single items on various self-report measures. These “other” symptoms can be further categorized into “other mood-related outcomes,” including hypomania,^17,26,28,30^ psychasthenia,^17^ mood swings,^28^ and other mood.^42^ Across the 5 studies that examined “other mood” outcomes,^17,26,28,30,42^ the overall pattern in the associations suggests moderate to large effects as a result of exposure to chemicals, as evidenced in 3 studies. Specifically, hypomania was found to have a large strength of association with Agent Orange exposure^26^ and a moderate strength of association with dioxin,^17^ a chemical component of Agent Orange. Exposure to chemical weapons was found to have a large effect on “mood swings.”^28^ Two final “other mood” studies examined exposure to oil well fires or chemical weapons but did not report sufficient data to determine effect size.^28,42^ A second, broader category of other mental health symptoms explored associations with chemical exposures and was comprised of anger or irritability (included in 5 studies)^1,14,18,28,30^ and several other subscales related to hostility, helplessness, hysteria, avoidant, antisocial, narcissistic paranoid, somatoform, dependent, schizoid, and paranoia.^26^ Only 2 of the 5 studies looking at irritability outcomes and chemical exposures found associations; both were categorized as large effects. Two of these did not report sufficient data to determine effect size.^18,28^

Six studies examined composite outcomes of mental health symptoms and had varied findings. For a study looking at a wide range of Gulf War-related exposures with a combination of sleep disturbance and depressed mood, no specific individual exposure was found to be associated with a specific outcome,^23^ yet a composite exposure score was associated with increased likelihood of sleep disturbance and depressed mood. In another study, the Mental Health composite score, as measured by the SF-12, was not found to have an association with a composite Deployment Risk and Resilience Inventory- II exposure score.^21^ Another study looked globally at the development of GWI symptoms, with a range of exposures including chemical weapons, pesticides, smoke from oil well fires, and found a range of large to small strength of association.^50^ Another study looked at the association between cumulative days of exposure to burn pits (0 days, 1-56 days, 57-131 days, 132-209 days, >209 days) and the development of CMI and did not find an association.^54^ Another looked at exposure to pesticides and found a small association with a higher score on a composite psychiatric health inventory, which assessed inability to fall asleep, frequent periods of feeling depressed, and frequent periods of anxiety or nervousness.^49^ A final composite outcome (development of CMI) was examined in association with exposure to a combination of chemical, biological, and nuclear exposures, but insufficient data were reported to glean an association.^18^

#### Multiple Mental Health Conditions

Six studies explored the relationship between participants with any mental health diagnosis in relation to a number of different toxic exposures.^33,43–46,48^ Most of these studies found no significant relationships.^33,43–46,48^ For pesticides, the composite mental health diagnosis was significantly related to insect repellent but was not associated with pesticide-treated uniforms or other chemicals; effect sizes were not reported.^44,48^ One study did detect a significant relationship with pesticides but with small effect.^43^ For the air pollution exposure category, the composite mental health diagnosis was significantly associated with automobile fumes,^48^ smoke screens, and industrial pollution,^48^ but it was not significantly associated with smoke from oil fires,^44,48^ burn pits,^48^ or tent heaters.^48^ Effect sizes were not reported. Ionizing radiation was not significantly associated, but depleted uranium was; however, strength of these associations was also not reported.^48^ Khamisiyah-related exposures to nerve agents,^45,46^ as well as mixed chemical, biological, and radiological agents^48^ were not associated with the composite mental health variable. Destroyed military vehicles, gas masks, and paints were not significantly associated with the variable but JP-8 and other fuels were (effect sizes not reported).^48^

### Neurocognitive Functioning

Although 22 studies discussed the relationship between toxic exposures and neurocognitive functioning, only 9 of these studies assessed neurocognitive functioning as an independent construct, which are synthesized below. Five of the 9 studies that analyzed neurocognitive functioning as a distinct variable looked at the association with chemicals.^15,26,31,32,55^ Most of these studies did not demonstrate a significant association between chemical exposures and neurocognitive functioning. Yet findings were mixed and only 3 analyses reported significant associations, but no effect sizes were reported.^15,31,32^ Veterans with a Camp Lejeune-related exposure (compared to those without) had a higher risk of developing Parkinson’s disease but were not at higher risk for other neurogenerative disorders (eg, dementia with Lewy bodies, multiple system atrophy, progressive supranuclear palsy).^15^ Veterans exposed to Agent Orange were twice as likely (than those not exposed) to develop a major neurocognitive disorder (dementia), even after adjusting for demographic variables and comorbid medical and psychiatric conditions (hazard ratio = 1.68, 95% CI [1.59, 1.77]).^32^ Another study of Agent Orange reported mixed findings. Veterans exposed to Agent Orange showed no difference on tests of executive functioning, attention/concentration, perceptual motor functioning, or decrements in global cognitive functioning.^55^ There were differences between Veterans with high Agent Orange exposure and those with lower levels of dioxin exposure for immediate and delayed memory and tactual memory.^55^ Effect sizes were not reported; study authors noted that these differences may not be clinically meaningful.^55^ When comparing Veterans with high versus low Agent Orange exposures, no significant differences were observed on tests of memory or intelligence.^26^ The last study assessed sulfur mustard-exposed Veterans and found that 90% or more performed within expectations on tasks of short- and long-term memory, thinking, judgment, insight, perception, and orientation, although language (not clearly defined) was “impaired” in 11.7% of the sample.^31^

The other 4 studies assessed a variety of Gulf War-related exposures,^30,49,57,59^ most of which found insignificant or negligible associations between the toxic exposure and neurocognitive function. No significant differences were found between those who were or were not exposed to oil well fires on tests of memory or attention/executive functioning after excluding individuals with invalid data based on a free-standing measure of performance validity.^30^ Similarly, another study found no association between a composite neuropsychological measured via a self-report questionnaire and exposure to anti-nerve gas pills and pesticides.^49^ There were differences for exposures related to debris from scuds, and poison gas or germ warfare, but the effect sizes were small.^49^ Another study assessed the association between a battery of 27 commonly used objective neuropsychological measures and multiple deployment-related exposures (eg, Khamisiyah munitions explosion, burning trash, diesel skin exposure, nerve gas, scud missile debris) and found no significant differences after statistical correction of multiple comparisons and excluding invalid data.^59^ Within group analyses, the study did show that a Khamisiyah-related exposure was significantly associated with worse sustained attention.^59^ The last study determined that the percentage of people who had “impaired cognition syndrome” (variable not defined) was greater in those who wore flea collars; however, this analysis was conducted on a sample of 5 participants.^57^ Overall results of these 9 studies suggest that certain chemical exposures (eg, Agent Orange) may increase the risk of developing dementia over time^15,32^; however, in non-geriatric cohorts, overall cognitive functioning was not significantly different from those without toxic exposures when utilizing objective data, correcting for multiple comparisons and utilizing performance validity measures.^26,30,31,49,55,59^

Figure 7 depicts the number of associations between toxic exposure type and objectively measured neurocognitive domains (ie, memory/learning, attention/concentration, perceptual/motor functioning, and executive functioning) analyzed in the current literature, and the reported effect sizes of each relationship analyzed, categorized by toxic exposure type. Relatively few tests have been conducted to examine the relationship between toxic exposure and these neurocognitive domains. Of tests conducted, most analyzed other exposure types not categorized elsewhere. Across all exposure types examined, test statistics were not reported, although in nearly all instances the authors characterized the results of these analyses as non-significant. No studies to date have examined the relationship between performance on objective neuropsychological measures and exposure to pesticides, multiple/mixed exposures, other air pollutants, other chemicals, or Gulf War-related exposures. Overall, conclusions are severely limited regarding the relationship between toxic exposure and memory/learning, attention/concentration, perceptual/motor functioning, and executive functioning outcomes.

The remaining 13 studies analyzed subjective cognitive complaints (eg, memory or concentration) as part of a combined multisystem physiological-psychological construct.^1,6,18,22,23,28,29,50,54,56,58,60,61^ As such, the relationship between toxic exposures and neurocognitive symptoms or diagnoses in these 13 studies could not be determined or described.

Figure 7 Association Sizes for Neurocognitive Functioning Across Exposures

Notes. Significance is only reported for those studies that did not report a summary estimate. Otherwise, significance is not incorporated into the overall effect size categories.