# METHODS

## REGISTRATION AND REVIEW

We preregistered this review protocol at the Open Science Framework (https://osf.io/cz9rd). We obtained external peer reviews of a draft of this report; their comments and author responses are in the Appendix.

## KEY QUESTIONS AND ELIGIBILITY CRITERIA

The following key questions were the focus of this review:

Key Question 1 | For which military service-related environmental and chemical toxic exposures have the co-occurrence of psychiatric conditions or symptoms been evaluated?
Key Question 2 | What is the range of prevalence, incidence, or association of co-occurring psychiatric conditions or symptoms among individuals with a history of military service-related environmental and/or chemical toxic exposures?

Study eligibility criteria are shown in the table below. Military exposures refers to contact with toxic agents acquired through ingestion, inhalation, or skin contact during military service.

| Eligibility Criteria
| Inclusion | Exclusion
Population | Active-duty military personnel, National Guard, reservists, or military Veterans; *Population must be at least 80% active-duty military or military Veterans OR report results separately for relevant population (and at least a total of 100 individuals from population of interest) | Individuals without current or prior service in the armed forces, inclusive of civilian military contractors and military family members; Animal studies
Exposure | Exposure to environmental and/or chemical toxins during military service; Exposures may have occurred before, during, or after deployment.; Exposures may be self-reported or verified.; Examples of environmental exposures include burn pits, radiation; Examples of chemical exposures include asbestos, Agent Orange | Other military-related exposures or injuries (eg, sexual trauma, race-based discrimination, traumatic brain injury, infectious diseases, blast events without also having a relevant environmental and/or chemical toxic exposure); Relevant exposures that occurred when not a member of the armed forces; PB pills and vaccines given during military service; Exposures assumed to be conferred because of job class but not explicitly stated (eg, radiation exposure among pilots)
Comparator | No history of toxic exposure or no comparator | Not applicable
Diagnoses/Symptoms of Interest | Psychiatric and neurocognitive symptoms and conditions, inclusive of related diagnoses (eg, MDD, GAD, PTSD, mild or major neurocognitive disorder, SUD) and symptoms (eg, executive functioning challenges, difficulty concentrating, memory challenges, slowed processing speed, suicidal behavior/ideation, sleep disturbance, aggression) | Physical or neurological symptoms or conditions (eg, headaches, muscle twitching)
Timing | Exposures must have occurred during military service (including reserves and National Guard service); Evaluation of the condition of interest may have occurred at any time after exposure | Exposures that occurred during the Korean War or WWII; Exposures that occurred to a Veteran after or before military service
Setting | Exposure may have occurred within the United States or abroad
Study Design | Observational: cohort, case-control, cross-sectional study | Modeling studies, case reports, case series, qualitative studies, conference abstracts; Observational studies with fewer than 100 participants from the populations of interest (see note above)
Publication Type | Peer-reviewed journals: primary studies, systematic reviews, meta-analyses | Narrative reviews, opinion pieces, letters, editorials, nonpeer-reviewed studies

Abbreviations. GAD=generalized anxiety disorder; MDD=major depressive disorder; PB=pyridostigmine bromide; PTSD=posttraumatic stress disorder; SUD=substance use disorder.

## SEARCHING AND SCREENING

In collaboration with a research librarian, we searched MEDLINE (via Ovid), Embase (via Elsevier), APA PsycINFO (via Ovid), and PTSDpubs (via ProQuest) through July 27^th^, 2023, using terms for military personnel, environmental exposures, and mental health and substance use (see Appendix for complete search strategies). Additional citations were identified from hand-searching reference lists and consultation with content experts. English-language titles, abstracts, and full-text articles were independently reviewed by 2 investigators, and disagreements were resolved by consensus.

## DATA ABSTRACTION

We screened all identified citations in duplicate by human reviewers at the title, abstract, and full-text level. Citations meeting eligibility criteria were included for extraction. Data extraction was completed by an individual investigator and overread by a second investigator. For KQ1 (evidence mapping of conditions and symptoms), we extracted key study characteristics as available that define the study population (eg, military service era, age, branch), exposure (eg, types, duration, dose, time since exposure), and types of co-occurring psychiatric or neurocognitive conditions/symptoms measured (eg, major depressive disorder [MDD], cognitive function, depressive symptoms). For KQ2 (evidence mapping of associations between exposures and psychiatric neurocognitive conditions/symptoms), we extracted the reported effect size of association (eg, odds ratio [OR], risk ratio [RR], and measures of variability).

## SYNTHESIS

Given the heterogeneity in mental health outcomes, we organized our results into 3 broad categories: psychiatric diagnoses (eg, PTSD), psychiatric symptoms (eg, feeling nervous and tense), and neurocognitive diagnoses and functioning (eg, memory/learning, attention/concentration). First, we distinguished between psychiatric diagnoses and psychiatric symptoms to reflect differences in how those categories might be interpreted, both for clinical and research purposes (eg, comparing scores of symptom scales to ICD codes from the electronic health record). We also described neurocognitive symptoms and diagnoses separately due to the differences in how neurocognitive measures are typically assessed (eg, using objective testing standards). Notably, all 3 categories reflect mental health outcomes but are described in these groups to assist with the interpretation of the results.

As this is an evidence mapping study, we did not attempt to aggregate estimates or generate summary effect estimates. For KQ1, we described key characteristics of the included studies, such as study design, patient demographics, exposure characteristics, and outcomes assessed. We investigated patterns across these characteristics to identify areas that are data rich and those warranting further investigation. We sought to identify if there were types of exposures or types of mental health conditions and symptoms with limited or no available literature (ie, gap analysis). We then employed visual approaches to organize and display key patterns across included studies.

For KQ2, we abstracted effect sizes when possible, and categorized the magnitude of the effect as none, small, medium or large, in line with established guidelines in the literature (Table 1).^16^ We then grouped estimates for distinct psychiatric and neurocognitive conditions and symptoms by exposure type. We reported ranges of study effect sizes across these groups.

- When a single study reported more than 1 measured association between the same exposure and outcome, we counted effect sizes (eg, 2 none vs 1 small vs 4 large) and prioritized the most common effect size (eg, large).
- If there was more than 1 exposure level (eg, 2 vs 6 days), we counted effect sizes within the most extreme exposure level (eg, highest number of days = 6 days) and used the most commonly occurring association for that exposure level as the size of the effect estimate.
- While not commonly reported, when there were different routes of exposure (eg, inhalation, skin absorption), each route of toxic exposure was considered a unique toxic exposure.

Table 1 Effect Estimate and Effect Size Coding Schema

Effect Size Description | OR/RR | SMD/d | β | R ^2^ | F
No association | <1.2 | <0.2 | <0.1 | <0.01 | <0.10
Small | 1.2-1.5 | 0.2-0.5 | 0.1-0.25 | 0.01-0.02 | 0.10-0.25
Moderate | 1.5-2.0 | 0.5-0.8 | 0.25-0.5 | 0.02-0.14 | 0.25-0.40
Large | >2.0 | >0.8 | >0.5 | >0.14 | >0.40

Notes. β=standardized regression coefficient; d=Cohen’s d; F=F statistic; OR=odds ratio; R^2^=coefficient of determination; RR=risk ratio, SMD=standardized mean difference.

Exposures were coded using the structure described in Table 2. There are likely many ways to group exposures. Given the lack of information provided in the included studies regarding route of exposure, we grouped similar chemical types together (eg, studies reporting JP-8/diesel exposure grouped together regardless of air or skin exposure due to lack of information).

Table 2 Exposure Category Coding Schema

Air Pollution
a. Oil well fire; b. Burn pits; c. Other air pollution exposures not otherwise specified
Chemicals
a. Chemical weapons; b. Herbicides (ie, Agent Orange); c. Pesticides; d. Camp Lejeune contaminated water exposure (ie, trichloroethylene, tetrachloroethylene, vinyl chloride, and/or benzene); e. Khamisiyah-related exposures; f. Other chemical exposures not otherwise specified
Heavy Metals
Radiation
a. Depleted uranium; b. Other radiation exposures not otherwise specified
Multiple Exposures/Mixed Exposures
a. Gulf War-related exposures (broadly defined); b. Khamisiyah-related exposure (if truly multiple); c. Other mixed exposures not otherwise specified
Other Exposures (Not Otherwise Captured in Categories 1-5)
a. JP-8 and/or diesel (including skin and/or fumes); b. Other exposures not otherwise specified

Notes. Primary exposure categories encompassed more unique exposures than those with a special interest subcategory label. Any exposures that did not get a subcategory designation are captured in the results section and figures under the primary exposure category (eg, air pollution).

There are many ways to group psychiatric and neurocognitive symptoms given that many symptoms are present across multiple diagnoses. Table 3 and the Appendix describe the coding schema we used for this evidence mapping study.

Table 3 Psychiatric and Neurocognitive Symptom and Diagnosis Coding Schema

Psychiatric Symptoms and Diagnosis
Depression Symptoms and Diagnosis | Depressive disorders, major depressive disorder (MDD), depressed mood, crying easily
Anxiety Symptoms and Diagnosis | Anxiety disorders, generalized anxiety disorders (GAD), anxiety symptoms, obsessive-compulsive disorder (OCD), hypochondriasis, nervous/tense
PTSD | Posttraumatic stress disorder (PTSD), posttraumatic stress symptoms
Substance Misuse | Substance use, substance-related and addictive disorders (excludes tobacco)
Suicidal Ideation and Behaviors | Suicidal ideation, suicidal self-directed violence, death by suicide
Hypersomnolence/Trouble Sleeping | Hypersomnolence/trouble sleeping, sleep-wake disorders
Other | Psychosis-related symptoms, adjustment disorder, somatic symptom disorders, schizophrenia and psychotic disorders, bipolar and related disorders
Neurocognitive Functioning
Symptom Domains of Neurocognition | Memory/learning (eg, short- and long-term recall and recognition); attention/concentration (eg, sustained attention, divided attention, selective attention, processing speed); executive functioning (eg, planning, organizing, decision-making, working memory, mental flexibility); perceptual-motor functioning (eg, visuospatial, constructional praxis); language (eg, expressive, receptive)
Neurocognitive Diagnoses | Major neurocognitive disorder (dementia), mild neurocognitive disorder (mild cognitive impairment)
Other Neurocognitive Variables | Other single outcome not otherwise specified (eg, “impaired cognition syndrome,” “confusion”); combined multidomain outcome (eg, mood and concentration, “composite neuropsychological variable,” “memory and attention”)

We included studies that reported composite outcomes of neuropsychiatric symptoms and physical symptoms. For the KQ2 synthesis, we did not include these studies unless the psychiatric symptoms were disaggregated in the primary study.

Of note, our intent was to define the co-occurrence of relevant conditions and symptoms, but not to establish causation. We mapped the patterns of associations across the included studies and provide visual displays of the exposure and co-occurrence of psychiatric or neurocognitive symptoms and disorders.

## STRENGTH OF EVIDENCE AND RISK OF BIAS ASSESSMENT

As this is an evidence map, we did not evaluate the risk of bias of individual studies or the overall strength of evidence.