# BACKGROUND

Across all military eras, U.S. service members have been exposed to toxic biological and chemical agents (eg, pesticides, herbicides, chemical weapons), airborne hazards (eg, burn pits, diesel fumes), depleted uranium and other radioactive materials, and several other hazards.^1–4^ Many toxic exposures can be experienced in all military eras, such as exposure to heat, infectious disease, occupational hazards, noise, and various chemicals. Certain exposures are limited to specific eras. These include exposures to the herbicide and defoliant Agent Orange among Vietnam War^5^ Veterans and exposure to chemical weapons (such as sarin via the Khamisiyah Munitions Depot demolition) and oil well fires among Veterans of the 1990-1991 Persian Gulf War.^6,7^ Veterans of the wars in Iraq and Afghanistan during Operation Desert Storm and Operations Iraqi and Enduring Freedom were likely exposed to harsh environmental conditions (eg, extreme heat, sand), and may have been exposed to chemical warfare agents, depleted uranium, and oil well fires.

Outside of conflict situations, service members can experience occupational exposure to a wide range of toxic agents, including diesel, jet propellants (eg, JP-8), lead, chemical solvents, fire retardants, and radiation.^8,9^ Other toxic exposures are linked to military bases, such as exposure to water contaminated with industrial solvents (eg, trichloroethylene, perchloroethylene) and benzene from leaking underground fuel storage tanks at U.S. Marine Corps Base Camp Lejeune in North Carolina between 1953 to 1987. Exposure to these agents while stationed at Camp Lejeune has been associated with at least 16 adverse health conditions (eg, female infertility, esophageal cancers, liver cancer, Parkinson’s disease).^10^

Recognizing the negative health effects of toxic exposures during military service,^3,4,11^ in 2022 the Biden administration passed the Sergeant First Class (SFC) Heath Robinson Honoring Our Promise to Address Comprehensive Toxics (PACT) Act.^12^ The PACT Act expanded and extended VA health care eligibility for Veterans with conditions presumed to be caused by toxic exposure that occurred during military service or who participated in a toxic exposure risk activity (TERA; any activities during military service that potentially expose service members to toxic substances such as handling hazardous materials like pesticides). As of September 2023, more than 4.3 million Veterans had been screened for a military toxic exposure. Of these, 43% (1,864,826) endorsed at least 1 potential exposure and 8.4% (368,250) endorsed more than 1 exposure.^12^

The PACT Act has also expanded eligibility for mental health and counseling services to Veterans who were in theater or potentially exposed to toxic agents during military service.^13^ A considerable amount of research has been conducted on associations between military exposures and subsequent psychiatric conditions and symptoms.^14,15^ Yet available evidence spans several military eras and examines a diverse range of exposures and psychiatric and neurocognitive outcomes, with limited synthesis conducted to date. To begin to address this gap, we used an evidence mapping methodology to organize and describe the current state of the peer-reviewed literature on the associations between toxic exposures during military service and mental, behavioral, and neuropsychiatric health issues (ie, psychiatric conditions or symptoms, or neurocognitive functioning). The goals of this report are to assist VA clinical teams in providing evidence-informed care to Veterans with psychiatric concerns who present during toxic exposure screenings and in developing national guidance for approaches to screening, assessment, and treatment related to these concerns.