# ABBREVIATIONS TABLE

Abbreviation: Definition
BDI: Beck Depression Inventory
CMI: Chronic multi-symptom illness
DSM: Diagnostic and Statistical Manual of Mental Disorders
GHQ: Global Health Questionnaire
ICS: International Classification of Diseases
KQ: Key question
MDD: Major depressive disorder
MCMI: Millon Clinical Multiaxial Inventory
MMPI: Minnesota Multiphasic Personality Inventory
NR: Not reported
OR: Odds ratio
OEF: Operation Enduring Freedom
OIF: Operation Iraqi Freedom
OND: Operation New Dawn
PACT: Heath Robinson Honoring Our Promise to Address Comprehensive Toxics
PB: Pyridostigmine bromide
POMS: Profile of Mood States-Depression
RR: Risk ratio
SFC: Sergeant First Class
SUDs: Substance use disorders
TEP: Technical expert panel
TERA: Toxic exposure risk activity
VHA: Veterans Health Administration