# REFERENCES

1 Privitera M, Weisman R, Cerulli C, Violence toward mental health staff and safety in the work environment. Occup Med (Lond). 2005 Sep;55(6):480–6. doi: 10.1093/occmed/kqi110. PMID: 15923198.15923198
2 de Looff P, Didden R, Embregts P, Burnout symptoms in forensic mental health nurses: Results from a longitudinal study. Int J Ment Health Nurs. 2019 Feb;28(1):306–17. doi: 10.1111/inm.12536. PMID: 30156026.30156026
3 Mento C, Silvestri MC, Bruno A, Workplace violence against healthcare professionals: A systematic review. Aggression and Violent Behavior. 2020 2020/03/01/;51:101381. doi: 10.1016/j.avb.2020.101381.
4 Weltens I, Bak M, Verhagen S, Aggression on the psychiatric ward: prevalence and risk factors. A systematic review of the literature. PLoS One. 2021;16(10):e0258346. doi: 10.1371/journal.pone.0258346. PMID: 34624057.34624057
5 Garriga M, Pacchiarotti I, Kasper S, Assessment and management of agitation in psychiatry: expert consensus. World J Biol Psychiatry. 2016;17(2):86–128. doi: 10.3109/15622975.2015.1132007. PMID: 26912127.26912127
6 National Collaborating Centre for Mental Health. National Institute for Health and Care Excellence: Guidelines. Violence and aggression: Short-term management in mental health, health and community settings: Updated edition. London: British Psychological Society (UK)© The British Psychological Society & The Royal College of Psychiatrists; 2015.
7 Fisher WA. Restraint and seclusion: a review of the literature. Am J Psychiatry. 1994 Nov;151(11):1584–91. doi: 10.1176/ajp.151.11.1584. PMID: 7943445.7943445
8 Legal Information Institute. 42 CFR § 482.13 - Condition of participation: patienťs rights. Cornell Law School. https://www.law.cornell.edu/cfr/text/42/482.13. Accessed on Mar 8, 2023.
9 Chieze M, Clavien C, Kaiser S, Coercive measures in psychiatry: A review of ethical arguments. Front Psychiatry. 2021;12:790886. doi: 10.3389/fpsyt.2021.790886. PMID: 34970171.34970171
10 Bergk J, Einsiedler B, Steinert T. Feasibility of randomized controlled trials on seclusion and mechanical restraint. Clin Trials. 2008;5(4):356–63. doi: 10.1177/1740774508094405. PMID: 18697850.18697850
11 Chieze M, Hurst S, Kaiser S, Effects of seclusion and restraint in adult psychiatry: A systematic review. Front Psychiatry. 2019;10:491. doi: 10.3389/fpsyt.2019.00491. PMID: 31404294.31404294
12 Muralidharan S, Fenton M. Containment strategies for people with serious mental illness. Cochrane Database Syst Rev. 2006 Jul 19(3):Cd002084. doi: 10.1002/14651858.CD002084.pub2. PMID: 16855984.16855984
13 Sailas E, Fenton M. Seclusion and restraint for people with serious mental illnesses. Cochrane Database Syst Rev. 2000;2000(2):Cd001163. doi: 10.1002/14651858.Cd001163. PMID: 10796606.10796606
14 Brown JS, Tooke SK. On the seclusion of psychiatric patients. Soc Sci Med. 1992 Sep;35(5):711–21. doi: 10.1016/0277-9536(92)90009-f. PMID: 1439921.1439921
15 Georgieva I, Mulder CL, Wierdsma A. Patients' preference and experiences of forced medication and seclusion. Psychiatr Q. 2012 Mar;83(1):1–13. doi: 10.1007/s11126-011-9178-y. PMID: 21516449.21516449
16 Tannsjo T. The convention on human rights and biomedicine and the use of coercion in psychiatry. J Med Ethics. 2004 Oct;30(5):430–4. doi: 10.1136/jme.2002.000703. PMID: 15467070.15467070
17 El-Badri S, Mellsop G. Patient and staff perspectives on the use of seclusion. Australas Psychiatry. 2008 Aug;16(4):248–52. doi: 10.1080/10398560802027302. PMID: 18608169.18608169
18 Steinert T, Birk M, Flammer E, Subjective distress after seclusion or mechanical restraint: one-year follow-up of a randomized controlled study. Psychiatr Serv. 2013 Oct;64(10):1012–7. doi: 10.1176/appi.ps.201200315. PMID: 23771400.23771400
19 Guzmán-Parra J, Aguilera-Serrano C, García-Sanchez JA, Experience coercion, post-traumatic stress, and satisfaction with treatment associated with different coercive measures during psychiatric hospitalization. Int J Ment Health Nurs. 2019 Apr;28(2):448–56. doi: 10.1111/inm.12546. PMID: 30239098.30239098
20 Kersting XA K, Hirsch S, Steinert T. Physical harm and death in the context of coercive measures in psychiatric patients: A systematic review. Front Psychiatry. 2019;10:400. doi: 10.3389/fpsyt.2019.00400. PMID: 31244695.31244695
21 Steinert T, Bergbauer G, Schmid P, Seclusion and restraint in patients with schizophrenia: clinical and biographical correlates. J Nerv Ment Dis. 2007 Jun;195(6):492–6. doi: 10.1097/NMD.0b013e3180302af6. PMID: 17568297.17568297
22 Whitecross F, Seeary A, Lee S. Measuring the impacts of seclusion on psychiatry inpatients and the effectiveness of a pilot single-session post-seclusion counselling intervention. Int J Ment Health Nurs. 2013 Dec;22(6):512–21. doi: 10.1111/inm.12023. PMID: 23682907.23682907
23 SAMHSA Substance Abuse and Mental Health Services Administration. National Guidelines for Behavioral Health Crisis Care Best Practice Toolkit. 2020. https://www.samhsa.gov/sites/default/files/national-guidelines-for-behavioral-health-crisis-care-02242020.pdf. Accessed on Mar 8, 2023.
24 De Cuyper K, Vanlinthout E, Vanhoof J, Best practice recommendations on the application of seclusion and restraint in mental health services: An evidence, human rights and consensus-based approach. J Psychiatr Ment Health Nurs. 2022 Dec 24. doi: 10.1111/jpm.12890. PMID: 36565433.36565433
25 Grantham D. Psych hospitals adopt core measures: the Joint Commission's release of HBIPS measures caps decade-long partnership with behavioral health. Behavioral Healthcare. 2010;30(10).
26 Shields MC, Rosenthal MB. Quality of inpatient psychiatric care at VA, other Government, nonprofit, and for-profit hospitals: A comparison. Psychiatr Serv. 2017 Mar 1;68(3):225–30. doi: 10.1176/appi.ps.201600074. PMID: 27745537.27745537
27 Staggs VS. Variability in psychiatric facility seclusion and restraint rates as reported on hospital compare site. Psychiatr Serv. 2020 Sep 1;71(9):893–8. doi: 10.1176/appi.ps.202000011. PMID: 32487008.32487008
28 Substance Abuse and Mental Health Services Administration (SAMHSA). Promoting Alternatives to the Use of Seclusion and Restraint—Issue brief #1: A National Strategy to Prevent Seclusion and Restraint in Behavioral Health Services U.S. Department of Health and Human Services. Rockville, MD: 2010. https://www.samhsa.gov/sites/default/files/topics/trauma_and_violence/seclusion-restraints-1.pdf
29 Center for Medicaid and State Operations/Survey & Certification Group. Hospitals – Restraint/Seclusion Interpretive Guidelines & Updated State Operations Manual (SOM) Appendix A. In: Department of Health & Human Services CfMMS, editor; 2008.
30 U.S. Department of Veterans Affairs VHA. Handbook 1160.06. Inpatient Mental Health Services Handbook.; 2013.
31 Bowers L. Safewards: a new model of conflict and containment on psychiatric wards. J Psychiatr Ment Health Nurs. 2014 Aug;21(6):499–508. doi: 10.1111/jpm.12129. PMID: 24548312.24548312
32 Väkiparta L, Suominen T, Paavilainen E, Using interventions to reduce seclusion and mechanical restraint use in adult psychiatric units: an integrative review. Scand J Caring Sci. 2019 Dec;33(4):765–78. doi: 10.1111/scs.12701. PMID: 31058332.31058332
33 Wallace BC, Small K, Brodley CE, Deploying an interactive machine learning system in an evidence-based practice center: abstrackr. Proceedings of the 2nd ACM SIGHIT international health informatics symposium; 2012.
34 World Bank. High income. 2022. https://data.worldbank.org/country/XD. Accessed on Sept 16, 2022.
35 Michie S, van Stralen MM, West R. The behaviour change wheel: a new method for characterising and designing behaviour change interventions. Implement Sci. 2011 Apr 23;6:42. doi: 10.1186/1748-5908-6-42. PMID: 21513547.21513547
36 Sterne JA, Hernán MA, Reeves BC, ROBINS-I: a tool for assessing risk of bias in non-randomised studies of interventions. BMJ. 2016 Oct 12;355:i4919. doi: 10.1136/bmj.i4919. PMID: 27733354.27733354
37 Sterne JA C, Savović J, Page MJ, RoB 2: A revised tool for assessing risk of bias in randomised trials. BMJ. 2019 Aug 28;366:l4898. doi: 10.1136/bmj.l4898. PMID: 31462531.31462531
38 Guyatt GH, Oxman AD, Vist GE, GRADE: an emerging consensus on rating quality of evidence and strength of recommendations. BMJ. 2008 Apr 26;336(7650):924–6. doi: 10.1136/bmj.39489.470347.AD. PMID: 18436948.18436948
39 American Psychiatric Nurses Association. APNA Position Statement on the Use of Seclusion and Restraint.
40 Ashcraft L, Bloss M, Anthony WA. Best practices: the development and implementation of "no force first" as a best practice. Psychiatr Serv. 2012;63(5):415–7. doi: 10.1176/appi.ps.20120p415. PMID: 22549524.22549524
41 Clement J. Zablocki VA Medical Center. Restraint and seclusion. 2021.
42 Iwamasa GY, Czekanski ER. Welcome to the Inpatient Seclusion and Restraint Reduction Toolkit. 2018.
43 Iwamasa GY, Czekanski ER. VHA Seclusion and restraint reduction toolkit. 2018.
44 VA Northern California Health Care System. Response to behavioral emergencies or “code green” in the Behavioral Health Inpaient Care Unit (BHICU).
45 Wale JB, Belkin GS, Moon R. Reducing the use of seclusion and restraint in psychiatric emergency and adult inpatient services- improving patient-centered care. Perm J. 2011 Spring;15(2):57–62. doi: 10.7812/tpp/10-159. PMID: 2184192721841927.
46 Hochstrasser L, Fröhlich D, Schneeberger AR, Long-term reduction of seclusion and forced medication on a hospital-wide level: implementation of an open-door policy over 6 years. Eur Psychiatry. 2018 Feb;48:51–7. doi: 10.1016/j.eurpsy.2017.09.008. PMID: 29331599.29331599
47 Hunter DE, Buick WP, Wellington T, Initial evaluation of reorganized hospitalization services in a community mental health center. Hosp Community Psychiatry. 1993 Mar;44(3):271–5. doi: 10.1176/ps.44.3.271. PMID: 8444440.8444440
48 Jenkins O, Dye S, Foy C. A study of agitation, conflict and containment in association with change in ward physical environment. Journal of Psychiatric Intensive Care. 2015;11(1):27–35. doi: 10.1017/S1742646414000065.
49 Rohe T, Dresler T, Stuhlinger M, [Architectural modernization of psychiatric hospitals influences the use of coercive measures]. Nervenarzt. 2017 Jan;88(1):70–7. doi: 10.1007/s00115-015-0054-0. PMID: 26820456.26820456
50 Bowers L, Flood C, Brennan G, A replication study of the city nurse intervention: reducing conflict and containment on three acute psychiatric wards. J Psychiatr Ment Health Nurs. 2008 Nov;15(9):737–42. doi: 10.1111/j.1365-2850.2008.01294.x. PMID: 18844799.18844799
51 Forster PL, Cavness C, Phelps MA. Staff training decreases use of seclusion and restraint in an acute psychiatric hospital. Arch Psychiatr Nurs. 1999 Oct;13(5):269–71. doi: 10.1016/s0883-9417(99)80037-5. PMID: 10565060.10565060
52 Haefner J, Dunn I, McFarland M. A quality improvement project using verbal deescalation to reduce seclusion and patient aggression in an inpatient psychiatric unit. Issues Ment Health Nurs. 2021 Feb;42(2):138–44. doi: 10.1080/01612840.2020.1789784. PMID: 32749904.32749904
53 Azuela G. The implementation and impact of sensory modulation in Aotearoa New Zealand adult acute mental health services: Two organisational case studies; 2019.
54 Cummings KS, Grandfield SA, Coldwell CM. Caring with comfort rooms. Reducing seclusion and restraint use in psychiatric facilities. J Psychosoc Nurs Ment Health Serv. 2010 Jun;48(6):26–30. doi: 10.3928/02793695-20100303-02. PMID: 20349887.20349887
55 Lloyd C, King R, Machingura T. An investigation into the effectiveness of sensory modulation in reducing seclusion within an acute mental health unit. Advances in Mental Health. 2014 2014/08/01;12(2):93–100. doi: 10.1080/18374905.2014.11081887.
56 Novak T, Scanlan J, McCaul D, Pilot study of a sensory room in an acute inpatient psychiatric unit. Australas Psychiatry. 2012 Oct;20(5):401–6. doi: 10.1177/1039856212459585. PMID: 23014117.23014117
57 Sivak K. Implementation of comfort rooms to reduce seclusion, restraint use, and acting-out behaviors. J Psychosoc Nurs Ment Health Serv. 2012 Feb;50(2):24–34. doi: 10.3928/02793695-20110112-01. PMID: 22439145.22439145
58 Smith S, Jones J. Use of a sensory room on an intensive care unit. J Psychosoc Nurs Ment Health Serv. 2014 May;52(5):22–30. doi: 10.3928/02793695-20131126-06. PMID: 24305908.24305908
59 Zimmermann DP S. Use of a serenity room for sensory modulation. Irvine, California: Brandman University; 2020.
60 Abderhalden C, Needham I, Dassen T, Structured risk assessment and violence in acute psychiatric wards: randomised controlled trial. Br J Psychiatry. 2008 Jul;193(1):44–50. doi: 10.1192/bjp.bp.107.045534. PMID: 18700217.18700217
61 Blair EW, Woolley S, Szarek BL, Reduction of seclusion and restraint in an inpatient psychiatric setting: A pilot study. Psychiatr Q. 2017 Mar;88(1):1–7. doi: 10.1007/s11126-016-9428-0. PMID: 26897657.26897657
62 Clarke DE, Brown AM, Griffith P. The Brøset Violence Checklist: clinical utility in a secure psychiatric intensive care setting. J Psychiatr Ment Health Nurs. 2010 Sep;17(7):614–20. doi: 10.1111/j.1365-2850.2010.01558.x. PMID: 20712684.20712684
63 Harrington A, Darke H, Ennis G, Evaluation of an alternative model for the management of clinical risk in an adult acute psychiatric inpatient unit. Int J Ment Health Nurs. 2019 Oct;28(5):1099–109. doi: 10.1111/inm.12621. PMID: 31206989.31206989
64 Manning T, Bell SB, Dawson D, The utilization of a rapid agitation scale and treatment protocol for patient and staff safety in an inpatient psychiatric setting. Psychiatr Q. 2022 Sep;93(3):915–33. doi: 10.1007/s11126-022-10001-y. PMID: 36006571.36006571
65 Trauer T, Hamilton B, Rogers C, Evaluation of the effect of a structured intervention for the management of behavioural disturbance on the level of seclusion in an acute psychiatric inpatient ward. Journal of Psychiatric Intensive Care. 2010;6(2):91–100. doi: 10.1017/S1742646410000026.
66 van de Sande R, Nijman HL, Noorthoorn EO, Aggression and seclusion on acute psychiatric wards: effect of short-term risk assessment. Br J Psychiatry. 2011 Dec;199(6):473–8. doi: 10.1192/bjp.bp.111.095141. PMID: 22016437.22016437
67 Blair M, Moulton-Adelman F. The engagement model for reducing seclusion and restraint: 13 years later. J Psychosoc Nurs Ment Health Serv. 2015 Mar;53(3):39–45. doi: 10.3928/02793695-20150211-01. PMID: 25751828.25751828
68 Boumans CE, Egger JI, Souren PM, Reduction in the use of seclusion by the methodical work approach. Int J Ment Health Nurs. 2014 Apr;23(2):161–70. doi: 10.1111/inm.12037. PMID: 23890418.23890418
69 Bowers L, James K, Quirk A, Reducing conflict and containment rates on acute psychiatric wards: The safewards cluster randomised controlled trial. Int J Nurs Stud. 2015 Sep;52(9):1412–22. doi: 10.1016/j.ijnurstu.2015.05.001. PMID: 26166187.26166187
70 McDonagh J RC, Valvano M, York J, Koval R, Wainright F. Inpatient Recovery Programming. 2019.
71 Ralph H. Johnson VA Medical Center. Mental health inpatient recovery program.Veterans Affairs; 2019.
72 Dickens GL, Tabvuma T, Frost SA. Safewards: changes in conflict, containment, and violence prevention climate during implementation. Int J Ment Health Nurs. 2020 Dec;29(6):1230–40. doi: 10.1111/inm.12762. PMID: 32691495.32691495
73 Hellerstein DJ, Staub AB, Lequesne E. Decreasing the use of restraint and seclusion among psychiatric inpatients. J Psychiatr Pract. 2007 Sep;13(5):308–17. doi: 10.1097/01.pra.0000290669.10107.ba. PMID: 17890979.17890979
74 Khadivi AN, Patel RC, Atkinson AR, Association between seclusion and restraint and patient-related violence. Psychiatr Serv. 2004 Nov;55(11):1311–2. doi: 10.1176/appi.ps.55.11.1311. PMID: 15534024.15534024
75 Lewis M, Taylor K, Parks J. Crisis prevention management: a program to reduce the use of seclusion and restraint in an inpatient mental health setting. Issues Ment Health Nurs. 2009 Mar;30(3):159–64. doi: 10.1080/01612840802694171. PMID: 19291492.19291492
76 Noorthoorn EO, Janssen WA, Theunissen J, The power of day-to-day motivational techniques and family participation in reducing seclusion: A comparison of two admission wards with and without a seclusion prevention protocol. International Journal of Mental Health. 2008 2008/07/01;37(3):81–98. doi: 10.2753/IMH0020-7411370304.
77 Pollard R, Yanasak EV, Rogers SA, Organizational and unit factors contributing to reduction in the use of seclusion and restraint procedures on an acute psychiatric inpatient unit. Psychiatr Q. 2007 Mar;78(1):73–81. doi: 10.1007/s11126-006-9028-5. PMID: 17102932.17102932
78 Richmond I, Trujillo D, Schmelzer J, Least restrictive alternatives: do they really work? J Nurs Care Qual. 1996 Oct;11(1):29–37. doi: 10.1097/00001786-199610000-00010. PMID: 8936879.8936879
79 Stoll J, Westermair AL, Kübler U, A two-center pilot study on the effects of clinical ethics support on coercive measures in psychiatry. BMC Psychiatry. 2022 Jun 1;22(1):370. doi: 10.1186/s12888-022-04024-9. PMID: 35650555.35650555
80 Taxis JC. Ethics and praxis: alternative strategies to physical restraint and seclusion in a psychiatric setting. Issues Ment Health Nurs. 2002 Mar;23(2):157–70. doi: 10.1080/016128402753542785. PMID: 11901660.11901660
81 Välimäki M. Managing Patient Aggression in Mental Health Services. 2016. https://ClinicalTrials.gov/show/NCT02724748.
82 Välimäki M, Lantta T, Anttila M, An evidence-based educational intervention for reducing coercive measures in psychiatric hospitals: A randomized clinical trial. JAMA Netw Open. 2022 Aug 1;5(8):e2229076. doi: 10.1001/jamanetworkopen.2022.29076. PMID: 36040740.36040740
83 Välimäki M, Yang M, Normand SL, Study protocol for a cluster randomised controlled trial to assess the effectiveness of user-driven intervention to prevent aggressive events in psychiatric services. BMC Psychiatry. 2017 Apr 4;17(1):123. doi: 10.1186/s12888-017-1266-6. PMID: 28372555.28372555
84 Whitecross F, Lee S, Bushell H, Implementing a psychiatric behaviours of concern team can reduce restrictive intervention use and improve safety in inpatient psychiatry. Australas Psychiatry. 2020 Aug;28(4):401–6. doi: 10.1177/1039856220917072. PMID: 32391731.32391731
85 Zuehlke JB, Kotecki RM, Kern S, Transformation to a recovery-oriented model of care on a veterans administration inpatient unit. Psychiatr Rehabil J. 2016 Dec;39(4):361–3. doi: 10.1037/prj0000198. PMID: 27845534.27845534
86 Champagne T, Stromberg N. Sensory approaches in inpatient psychiatric settings: innovative alternatives to seclusion & restraint. J Psychosoc Nurs Ment Health Serv. 2004 Sep;42(9):34–44. doi: 10.3928/02793695-20040901-06. PMID: 15493494.15493494
87 Azuela G, Robertson L. The effectiveness of a sensory modulation workshop on health professional learning. The Journal of Mental Health Training, Education and Practice. 2016;11(5):317–31. doi: 10.1108/JMHTEP-08-2015-0037.
88 Champagne T. Sensory modulation & environment: Essential elements of occupation. Southamton, MA: Champagne Conferences & Consultation; 2008.
89 Sutton D NE. Sensory modulation in acute mental health wards: A qualitative study of staff and service users’ perspectives. The National Centre of Mental Health Research IaWDTP; 2011. https://openrepository.aut.ac.nz/items/bf3c9860-05eb-48df-88be-ba9b34b8f7c3
90 MacDaniel M. Comfort rooms: A preventative tool used to reduce to reduce the use of restraint and seclusion in facilities that serve individuals with mental illness. 2009. https://omh.ny.gov/omhweb/resources/publications/comfort_room/comfort_rooms.pdf
91 Alligood MR TA. Nursing Theorists and Their Work 7th ed. Maryland Heights, MO; 2010.
92 Hardesty S, Borckardt JJ, Hanson R, Evaluating initiatives to reduce seclusion and restraint. J Healthc Qual. 2007 Jul-Aug;29(4):46–55. doi: 10.1111/j.1945-1474.2007.tb00205.x. PMID: 17849680.17849680
93 U.S. Department of Veterans Affairs VHA. Design Guide for Inpatient Mental Health & Residential Rehabilitation Treatment Program Facilities 2021. https://www.cfm.va.gov/til/dGuide/dgMH.pdf
94 Ulrich RS, Bogren L, Gardiner SK, Psychiatric ward design can reduce aggressive behavior. Journal of Environmental Psychology. 2018 2018/06/01/;57:53–66. doi: 10.1016/j.jenvp.2018.05.002.
95 Cassidy E, Hill S, O'Callaghan E. Efficacy of a psychoeducational intervention in improving relatives' knowledge about schizophrenia and reducing rehospitalisation. Eur Psychiatry. 2001 Dec;16(8):446–50. doi: 10.1016/s0924-9338(01)00605-8. PMID: 11777734.11777734
96 Eldon Taylor C, Lopiccolo CJ, Eisdorfer C, Best practices: reducing rehospitalization with telephonic targeted care management in a managed health care plan. Psychiatr Serv. 2005 Jun;56(6):652–4. doi: 10.1176/appi.ps.56.6.652. PMID: 15939940.15939940
97 Tomita A, Herman DB. The impact of critical time intervention in reducing psychiatric rehospitalization after hospital discharge. Psychiatr Serv. 2012 Sep 1;63(9):935–7. doi: 10.1176/appi.ps.201100468. PMID: 22810163.22810163
98 Hoffmann TC, Glasziou PP, Boutron I, Better reporting of interventions: template for intervention description and replication (TIDieR) checklist and guide. BMJ. 2014 Mar 7;348:g1687. doi: 10.1136/bmj.g1687. PMID: 24609605.24609605