# ACKNOWLEDGMENTS

The authors are grateful to Gaelen Adam, MLIS for literature searching and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Marsden H. McGuire, MD, MBA
  Director
  Continuum of Care and General Mental Health; VA Central Office
- Gayle Y. Iwamasa, PhD HSPP
  National Director
  Inpatient Mental Health, OMHSP

## Technical Expert Panel

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Elizabeth Czekanski, DNP, MS, RN-BC, NE-BC, VHA-CM
  Mental Health Clinical Nurse Advisor; Office of Nursing Services
  Department of Veterans Affairs
- Wendy Leopoulos, MD
  Medical Director of Inpatient Mental Health Program; Mental Health Care Line
  Michael E. DeBakey VAMC
- Kelly Vance, MD, FACHE
  Director of Education and Informatics; Workplace Violence Prevention Programs
  VA Office of Mental Health and Suicide Prevention
- Jennifer Snow, MSN RN
  Assistant Chief; Quality, Safety, Value (QSV)
  Tennessee Valley Healthcare System

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence (see Appendix K for disposition of comments). Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center works to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.