# DISCUSSION

We identified 48 reports that described 43 protocols (7 reports described 6 protocols without evaluation and 41 reports described 37 studies that reported comparative data). Interventions were multicomponent and targeted multiple levels, actors, and determinants of both patient and staff behavior. Four comparative studies evaluated hospital/unit restructuring, 3 evaluated staff education/training, 7 evaluated sensory modulation/rooms, 7 evaluated risk assessment interventions, and 16 evaluated comprehensive/mixed interventions. All 6 non-comparative protocols involved comprehensive/mixed interventions. Episodes of seclusion was the most frequently evaluated outcome, followed by episodes of restraint and composite outcomes of seclusion and restraint. Key findings include the following:

- Hospital/unit restructuring
  - Hospital/unit restructuring protocols involved implementing an open-door policy, outfitting rooms with natural light, and a culture shift towards patient-centered and recovery-oriented care (ie, intervention function environmental restructuring).
  - Restructuring units to include architecturally positive elements and restructuring services (including, in some cases, implementing an open-door policy) may reduce episodes of seclusion, duration of seclusion, duration of restraint, and use of forced medication (low confidence).
  - It is unknown if restructuring units reduces episodes of restraint, other patient outcomes, and staff outcomes (insufficient evidence). The studies did not evaluate a composite measure of coercion.
- Staff education/training
  - Education/training interventions provided staff with de-escalation techniques and alternative strategies to seclusion and included intervention functions of persuasion, education, training, or modelling. Staffing was the primary resource associated with the interventions.
  - Staff training (eg, de-escalation, alternative strategies to seclusion, and preventing violence) may reduce staff injuries and as-needed medication use (low confidence).
  - It is unknown if staff training reduces episodes of seclusion, episodes of restraint, composite measures of coercion, and patient outcomes such as aggression (insufficient evidence). The studies did not evaluate duration of seclusion or restraint.
- Sensory modulation
  - Sensory modulation rooms involved creating a dedicated space to meet the multisensory needs of patients. The common intervention element was environmental restructuring followed by education, persuasion, enablement, and restrictions. Space and equipment to facilitate the intervention were the primary resources associated with sensory rooms.
  - Sensory/comfort rooms may reduce episodes of seclusion and forced medication use but may not affect duration of seclusion (low confidence).
  - It is unknown if sensory/comfort rooms reduce episodes of restraint, composite measures of coercion, patient outcomes (such as self-injury, patient-to-patient assault), and staff outcomes (patient-to-staff assault) (insufficient evidence). The studies did not report on duration of restraint.
- Risk assessment and management protocols
  - Risk assessment and management protocols involved using a structured tool to help staff identify potentially aggressive patients to direct clinical efforts. Risk assessment and management protocols included intervention functions of environmental restructuring, education, and training. Resource requirements included documentation and time staff spent to perform checks on patients.
  - Structured risk assessments that include the Brøset Violence Checklist may reduce episodes of seclusion, a composite measure of seclusion and, patient aggressive events (low confidence).
  - There is no evidence of differences in episodes of restraint, and duration of restraint may increase for interventions that include the Brøset Violence Checklist (low confidence).
  - It is unknown if incorporating the Brøset Violence Checklist reduces the duration of seclusion (insufficient evidence). The studies did not evaluate forced medication use or staff outcomes.
  - Investigator-developed or -modified risk assessment tools may reduce episodes and duration of restraint but not duration of seclusion (low confidence).
  - There is no evidence of differences in duration of seclusion or staff stratification for investigator-developed or -modified risk assessment tools (low confidence).
  - It is unknown if investigator-developed risk assessment tools reduce episodes of seclusion or other patient outcomes (insufficient evidence). The studies did not evaluate composite measures of coercion or forced medication use.
- Comprehensive/mixed interventions
  - Comprehensive/mixed protocols included intervention functions of education and training. Protocols often included elements of persuasion to reinforce staff education and environmental restructuring to change physical or social context of the wards. The most common resource needs to implement mixed interventions were documentation and staffing followed by programming.
  - The Steward's intervention may reduce a composite measure of coercion (restraint and seclusion and/or forced medication use) and patient conflicts (low confidence).
  - It is unknown if the Safewards intervention impacts staff outcomes (insufficient evidence). The studies did not evaluate episodes or duration of seclusion, episodes or duration of restraint, or episodes of forced medication use.
  - Other comprehensive interventions may reduce episodes of seclusion, duration of seclusion, duration of restraint, and episodes and duration of composite measures of coercion (low confidence).
  - There is no difference in episodes of restraint or forced medication use for other comprehensive interventions (low confidence).
  - It is unknown if other comprehensive interventions reduce other patient outcomes or staff outcomes (no conclusion).

## STRENGTHS AND LIMITATIONS OF THE EVIDENCE BASE

There is great interest from policymakers, hospital administrators, staff, and patients for effective alternatives to seclusion. One of the most reassuring findings of this review is the number of protocols we found that attempted to address this need, and the diversity of intervention functions identified within protocols, suggesting that intervention designers are building complex solutions to address a complex practice problem. For example, 8 of the 9 intervention functions were identified in efforts to reduce staff’s use of seclusion (education, persuasion, incentivization, training, restriction, environmental restructuring, modelling, and enablement), and 7 of the 9 intervention functions were identified in efforts to reduce patients’ aggressive behavior (education, persuasion, incentivization, training, restriction, environmental restructuring, and enablement). It is reassuring that two-thirds of interventions targeted both patients and staff to reduce the likelihood of precipitating behavior requiring seclusion or any alternatives. In such protocols, patients were provided with education on how to manage distress more effectively and were often enabled to do so through efforts to change or re-shift the patient-staff dynamic from one of control to collaboration. Patient-focused interventions also often included environmental changes to support patients to manage their emotions (eg, access to a sensory room) along with social changes to the ward culture. While the evidence supporting the effectiveness of protocols to reduce seclusion (or their component intervention functions) is limited due to the quality of the empirical designs (discussed below), the ethos of the interventions aligns with contemporary perspectives of patient-oriented recovery-focused mental health care.

An important limitation of the evidence base is the sparse reporting of outcomes of interest to stakeholders; namely outcomes of patient aggression, patient and staff injuries, and patient and staff satisfaction. While the content of these interventions suggests face validity that they may be preferred by patients (and possibly staff) compared to seclusion, there is insufficient evidence to justify this claim. Although outcomes of seclusion, restraint, or composite of both combined with or without forced medication use were reported frequently, they were not consistently reported in the same study, which made it challenging to evaluate trade-offs between reducing seclusion and other interventions. For example, we found that protocols with sensory modulation rooms may reduce episodes of seclusion, but their impact on episodes of restraint was unknown due to insufficient evidence. Conversely, some studies only reported seclusion and restraint as a composite outcome, which did not allow for direct comparison with other studies that reported seclusion and restraint distinctly.

Although multiple interventions show promise to reduce seclusion, findings need to be interpreted with caution. Only 4 of 37 comparative studies used a RCT design. Of the remaining 33 studies, 5 used a concurrent comparison design (often with non-comparable units as comparison) and 28 used a pre-post design. Overwhelmingly, many of these pre-post evaluations were characterized as quality improvement projects in which a hospital or unit implemented an intervention to achieve an administrative or policy goal to reduce seclusion. While some studies were very explicit in defining their theoretical or empirical basis for the design of their protocol, others were not and the rationale for the protocol appeared primarily driven by a hospital or policy recommendation or preference to reduce or eliminate seclusion. It is possible then, especially in the latter studies, that observed reductions in seclusion rates could be due to staff responding to administrative goals (or presumed pressure) rather than a specific mechanism of action being targeted by an intervention.^51,92^

A major limitation of the evidence was that all the studies relied on self-reported outcome data: staff were either the target or implementers of interventions and were also the outcome observers. In protocols with patient-directed interventions, they also implemented the intervention. Given that most interventions and quality improvement initiatives were explicit in their aims to reduce seclusion, it is feasible that staff could have either changed their behavior or measured their behavior differently to meet hospital or researcher expectations (ie, performance bias). Although it is difficult to change who observes and records coercion events for future studies, it is possible to modify or downplay intervention expectations to alleviate performance bias. For example, 1 RCT included in the review (of Safewards) randomized control wards to a physical activity program and led staff and patients in the unit to believe they were receiving the intervention condition (that would lead to reduced rates of seclusion), thereby countering potential for performance bias.^69^ Another limitation of available evidence is inconsistent outcome reporting: some studies reported rates of seclusion per number of admissions, others reported raw counts of events (with limited data on sample size), and others did not clearly specify units of time for duration-related outcomes. With respect to analysis, most NRCSs conducted crude (unadjusted) analyses and did not adequately account for confounding.

## STRENGTHS AND LIMITATIONS OF THE SYSTEMATIC REVIEW PROCESS

We followed contemporary standards for conducting systematic reviews. The systematic review was designed broadly to include all possible protocols to reduce seclusion but restricted to protocols that could be feasibly delivered in US health care settings. A strength of this review was our detailed coding of the intervention functions of the protocols. Coding in this way allowed us to see past intervention labels and key phrases to isolate the core of their hypothesized mechanisms of action (where reported) and who was being targeted. Our codes provided a structure to group the protocols into meaningful categories for subsequent syntheses and identified trends of intervention functions both within and across these categories. This coding can be used to inform future practice for units hoping to implement these interventions (or parts of them) or identify opportunities for future research (eg, untested or rarely used intervention functions).

This review has several limitations. We defined protocols as guidance documents or strategies as an alternative to seclusion. The operationalization of our definition of a protocol required the review team to make decisions about whether an intervention met our definition of a protocol; it is possible that we may have missed protocols in our operationalizing of our definition. Although we aimed to extract data on the resources needed to deliver an intervention, most studies did not explicitly document these data (eg, equipment or security needs), and we had to infer the resource needs based the description of the interventions. We sought to make minimal inferences and stay true to the data in the report. Finally, while we believe a strength of our review was the coding of interventions and grouping into conceptually similar categories, it is possible that the conclusions could change if groupings of interventions changed.

## APPLICABILITY

Although we restricted the review to studies conducted in settings that may be most applicable to inpatient mental health units in the US, it is important to note that unique elements of interventions and contexts in which they were applied may not generalize to all inpatient psychiatric hospitals. A strength of many of the studies was the extent to which the protocols were tailored to the local context, designed with stakeholder engagement to support their implementation (eg, staff and/or patients were invited to participate in understanding the problem and building solutions to address the problem).^47,51,54^ Safewards may offer the most generalizable intervention, given the comprehensive nature of the intervention and that evidence in support of the intervention comes from a RCT (it is well investigated, but few studies of Safewards met our review eligibility criteria). An important consideration in the applicability of these protocols is their associated resource needs. Although resource needs were less formally evaluated compared with clinical events, there is some evidence to suggest that they can at times be substantial and include increased personnel, equipment, and time for staff to complete training, deliver programming, or do additional documentation. Users of this report may consider implementing elements of the reviewed protocols (described in detail in Appendix H, with resource implications in Appendix I) that either map to shared clinical contexts (eg, the VA) or complement existing local protocols to reduce seclusion (eg, if staff education and training are already present, are there aspects of this that can be refined or additional elements such as staff modeling by expert peers or enablement of patients that can be added?).

## IMPLICATIONS FOR VA POLICY AND PRACTICE

We identified 4 pre-post studies conducted in the VA.^70,77,78,85^ All 4 studies evaluated comprehensive interventions that involved, at minimum, stafftraining and creating a patient-centered ward culture. Two studies specifically described protocols based on a recovery-oriented model of care, which align with the requirements in VHA Handbook 1160.06 (“inpatient mental health units also must provide a healing, recovery-oriented environment”).^30,70,85^ One of these studies was a conference poster presentation with limited information on methods and results.^70^ The 4 studies relied on self-reported outcome data, and only 1 study conducted regression analysis to adjust for confounding.^77^ All 4 studies reported large reductions in outcomes related to seclusion.

Consistent with requirements from VHA Handbook 1160.06 and the Design Guide for Inpatient Mental Health & Residential Rehabilitation Treatment Program Facilities,^93^ the studies we identified found that modifying the environment (eg, sensory rooms) reduced seclusion. However, we note that open-door polices may not be relevant to the VA context. VA inpatient mental health units should continue to view the environment as a component of treatment and make modifications as needed. For units in established facilities, this means ensuring that there are opportunities for patient-patient and patient-staff social interaction, meaningful activities, and private spaces for relaxation. As the VA constructs new facilities, it should consider constructing smaller units (ie, number of patients) with well-designed layouts incorporating natural light, effective acoustics management, and green space.^94^

As the VA aims to implement less restrictive interventions to manage conflict behaviors in inpatient units, there are opportunities for system-level approaches to monitor and evaluate efforts. VA-wide improvement efforts have already been implemented towards standardized documentation in the electronic health record, such as the Violence Risk Assessment; however, further opportunities exist which can include standardizing measures in the electronic medical record to document process (eg, use of seclusion) and outcomes (eg, aggression). Once data are uniformly reported in the electronic medical record, then it is possible to standardize reporting at system levels (eg, Medical Center, VISN, and national program offices) to evaluate trends and identify units with above/below average process and outcome measures. With standardized reporting of process and outcomes, VA could use its robust electronic medical record to conduct secondary database analyses to develop interventions to identify Veterans at high risk of being placed in seclusion or who exhibit conflict behaviors.

Although not covered in our review, several studies noted the importance of follow-up outpatient care as a feature of high quality inpatient mental health care. This is also highlighted in VHA Handbook 1160.08. Patients in inpatient mental health wards often have 1 or more readmissions after discharge. An aspect of care that was not covered by our review, but which could have an important role in reducing the use of seclusion, is to reduce the need for inpatient mental health care. As an integrated health system, the VA is positioned to ensure continuity between inpatient and outpatient mental health care.^95–97^ For example, VA programs such as the Mental Health Intensive Case Management focus on patients who frequently use VHA mental health inpatient and emergency services, with the goal of reducing hospital use and improving patient functioning, reducing symptoms, and minimizing substance use.

## IMPLICATIONS FOR RESEARCH

Multiple NRCSs and quality improvement studies have evaluated alternatives to seclusion. The literature had major methodological limitations, some of which may be easy to overcome. Most studies relied on data from medical records to conduct analysis and did not account for confounding variables. Future observational studies should account for confounders in their analyses by, at a minimum, conducting regression adjustment that includes patient characteristics that are also routinely captured in the electronic medical record. For hospitals that are part of large systems, there are opportunities to use electronic medical record data and quasi-experimental methods to compare units that do and do not implement interventions. Such larger studies should use more sophisticated methods to account for potential confounders such as propensity score matching or inverse probability weighting. Few studies reported outcomes by subgroups and there is an opportunity to use medical record data to identify effects of interventions for patients with specific diagnoses. There are also opportunities to improve the reporting of outcomes, such as reporting different forms of coercion as separate outcomes to allow practitioners and policy makers to understand the trade-offs (if any) between reducing seclusion and other forms of coercion. There are also opportunities to improve RCTs, such as conducting more RCTs with appropriate cluster randomized methods (design and analysis) and with appropriate attention and performance bias controls.^69^ Comparative evaluations could be improved by detailed reporting of the elements of their protocols via the use of standardized reporting guidelines (eg, the template for intervention description and replication [TIDieR]).^98^

## CONCLUSIONS

Despite numerous comparative studies, there are limited data on the benefits of seclusion and concern that the practice could cause harm. Restructuring units to include open wards or positive features, sensory/comfort rooms, structured risk assessments that include the Brøset Violence Checklist, and comprehensive/mixed interventions may reduce seclusion. Restructuring units may also reduce the use of restraints and forced medication. There is no difference in episodes of restraint for other comprehensive interventions or structured risk assessments that include the Brøset Violence Checklist. It is unknown if sensory modulation rooms reduce episodes of restraint. It is unknown if staff training alone or investigator-developed risk assessment tools reduce seclusion. These findings may generalize to the VA, which is already implementing several strategies demonstrating reductions in seclusion (eg, unit restructuring and comprehensive/mixed interventions). The literature was marked by methodological limitations. Opportunities for future research and practice include standardizing reporting of process and outcome measures in electronic medical records and conducting analyses that account for confounders.