# METHODS

## TOPIC DEVELOPMENT

We worked with representatives from OMHSP and our technical expert panel (TEP), which included individuals from OMHSP, the VA Office of Nursing Services, and VA Inpatient Mental Health Program, to refine the review scope and develop the key questions (KQs). We focus on studies that report protocols to reduce seclusion practices for adult patients in inpatient mental health units. We define protocols as guidance documents or strategies recommended or already employed as alternatives to seclusion. Protocols needed to include multiple components or a general overall policy to reduce seclusion. We define seclusion as the use of involuntary time restricted to a space physically removed from other patients.

## KEY QUESTIONS

- KQ1: What protocols have been described to reduce seclusion practices for adult patients in inpatient mental health units?
  - KQ1.1: What are the described resource needs (such as personnel and space needs) of these protocols?
- KQ2: What are the comparative effects of protocols to reduce seclusion practices on resource use, staff and unit practices, patient experiences, and staff experiences versus usual protocols?

## PROTOCOL

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (www.crd.york.ac.uk/PROSPERO/; registration number CRD42022363787).

## DATA SOURCES AND SEARCHES

We conducted a preliminary search in PubMed which was focused on Medical Subject Headings (MeSH) terms for patient isolation and inpatient mental health, together with free text synonyms for both (identified from experts and a list of known relevant publications). Searches were expanded to capture additional terms identified in preliminary screening.

For our final searches, we searched PubMed, Embase, the Cochrane Register of Clinical Trials, PsycINFO, CINAHL, cairn.info, and ClinicalTrials.gov from date of inception to September 6, 2022 (see Appendix A for complete search strategies). Additional citations were identified from hand-searching reference lists of relevant systematic reviews and consultation with content experts. In addition to the above, for KQ1 we contacted VA experts to request relevant protocols (published or grey literature) on strategies to reduce seclusion practices.

## STUDY SELECTION

Citations were uploaded into Endnote, where duplicates were removed. Remaining citations were uploaded into Abstrackr, abstract screening software (http://abstrackr.cebm.brown.edu).^33^ Title and abstracts were reviewed for eligibility by a team of 8 researchers. To ensure consistency and clarity of eligibility criteria, we held several pilot rounds of screening in which all team members screened the same set of titles and abstracts and any conflicts were resolved through discussion (Table 1). Subsequently, 2 independent reviewers screened titles and abstracts. Conflicts between screeners were resolved through group discussion or a third senior researcher.

Abstrackr uses machine learning algorithms to predict the likelihood that unscreened abstracts are relevant.^33^ Based on empirical evidence, we stopped screening when all remaining unscreened abstracts had a prediction value of <0.40 (on a 0–1 scale), and subsequently 400 abstracts in a row were rejected. Full text of potentially relevant citations were obtained and rescreened for eligibility using an evidence mapping process by 1 researcher with confirmation of excluded articles by a second senior researcher. Although qualitative studies did not meet our eligibility criteria, they were noted of interest to the stakeholders, and thus isolated for bibliographic purposes during full-text review.

For KQ1, our focus was on reporting the characteristics/features of protocols to reduce seclusion in general inpatient psychiatric units for patients ≥18 years of age. Eligible records were either organizational documents of protocols to reduce seclusion or primary studies that described a protocol to reduce seclusion. These records did not have to report outcomes. To ensure relevance to the VA setting, we only included protocols produced by organizations in the US or Canada or protocols intended to be implemented in these countries for KQ1. Records had to describe protocols with a callout of how these may differ from usual seclusion protocols.

For KQ2, eligible populations were patients ≥18 years of age with psychiatric conditions being treated in hospital inpatient units or the frontline staff who worked in these units. Our focus was on the effects (or comparative effects) of protocols to reduce seclusion. To be included, studies had to compare protocols to reduce seclusion to some form of comparison (eg, another protocol to reduce seclusion or “usual care”). Recognizing the challenges of conducting RCTs and non-randomized controlled studies (NRCS) with concurrent control groups, we allowed for the inclusion of pre-post studies (ie, same unit assessed before and after the implementation of the protocol) to satisfy these criteria. We only included protocols intended to be implemented in the US or other high-income countries.^34^

For both KQ1 and KQ2, studies were excluded if they included incarcerated or institutionalized populations, as these settings and populations were outside the scope of interest to our stakeholders.

Table 1 Inclusion and Exclusion Criteria

| Inclusion Criteria | Exclusion Criteria
Population | - KQs 1 & 2: Adults with psychiatric conditions admitted (voluntary/involuntary) and being treated in hospital inpatient units; - KQ2 (additional): Frontline staff and other psychiatric unit and hospital personnel | - Incarcerated; - Institutionalized
Intervention | - Psychiatric unit-level protocols to reduce seclusion practices; - Protocols to be defined by research study or organization guidance as strategies recommended (or already employed) as an alternative to seclusion. Protocols needed to include multiple components or a general overall policy to reduce seclusion (ie, not a single strategy only). | - KQs 1 and 2: Laws or regulations related to use/disuse of seclusion
Comparator | - KQ1: Not required explicitly (as KQ1 did not include an evaluation of protocols) but implicitly the protocols should be in contrast to seclusion practices.; - KQ2: Usual seclusion protocols (ie, no protocol directly aimed at reducing or minimizing seclusion); ○ Example comparisons include: same unit pre-intervention (ie, pre-post protocols to reduce seclusion) or concurrent controls from other units that do not use protocols to reduce seclusion.
Outcomes | - KQ1: Descriptions of protocols, with explicit callout of how these may differ from usual seclusion protocols; - KQ1.1: Center/unit/hospital resource use:; ○ Staffing needs and mix; ○ Environment (home-like vs clinical); ○ Programming (eg, meaningful activities); ○ Security personnel needs; ○ Space (eg, rooms) requirements; ○ Equipment needs; ○ Documentation needs (eg, patient engaged in treatment planning and update of treatment plan); ○ Staff debriefings; ○ Other direct medical use | - KQs 1.1 and 2: Dollar (or other currency) costs, hospital charges or payer costs, patient costs (direct or indirect), or other indirect costs/resources
Outcomes (continued) | - KQ2: Patient outcomes; ○ Injuries; ○ Aggressive incidents or behaviors; ○ Patient satisfaction with treatment (assessed post-hospitalization); ○ Psychiatric medication use, either as needed, urgent/emergency, scheduled, or forced; - KQ2: Staff outcomes; ○ Staff/personnel injuries (including physical, emotional, or other harms to staff); ○ Staff/personnel satisfaction with policy; ○ Debriefings (whether occurred and qualitative description); - KQ2: Process measures; ○ Characteristics of seclusion events; ■ Episodes of seclusion; ■ Episodes of restraint; ■ Time in seclusion (per inpatient stay, and per episode); ■ Time in restraint (per inpatient stay, and per episode); ○ Staffing; ■ Time to perform checks on patient; ■ Time to perform documentation; ■ Changes in other service provisions; ○ Center/unit/hospital resource use; ■ Staffing needs and mix; ■ Security personnel needs; ■ Space (eg, rooms) requirements; ■ Equipment needs; ■ Documentation needs; ■ Other direct medical costs
Timing | KQ1 : Published since 2012; KQ2: No restrictions
Setting | - In hospital inpatient units; - KQ1: Produced by North American organizations or implemented or intended to be implemented in North America only; - KQ2: High-income countries defined by the World Bank | - Emergency department, prisons, and outpatient settings; - KQ1: Not produced by organizations in the US or Canada or implemented or not intended to be implemented in US or Canada; - KQ2: Not intended to be implemented in US or other high-income countries
Study Design | - KQ1: Organizational documents of protocols to reduce seclusion or intervention and observational studies (only for protocol descriptions); - KQ2: Comparative studies (pre-post same unit or comparison of units), interventional or observational, prospective or retrospective, surveys with explicit comparison of intervention and comparator | - Case studies, opinion pieces, letters, editorials; - KQ1: Published before 2012

## DATA EXTRACTION AND ASSESSMENT

For both KQs 1 and 2, we extracted details about the organization/research group that produced the protocol (eg, country, organization, rationale, process) and specific protocol elements. As protocol elements may have varied depending on the target of the element (staff vs patient), we extracted elements for staff and patients separately. We categorized extracted protocol elements into 1 of 9 Intervention Functions defined by the behavior change wheel (BCW), which characterizes behavior change interventions.^35^ The framework is relevant to describing the protocols included in this review, as the protocols often tried to change behavior (staff, patients, or both) to reduce seclusion events. The 9 intervention functions include education, persuasion, incentivization, coercion, training, restriction, environmental restructuring, modelling, and enablement (Appendix B lists the intervention functions and their definitions). We also extracted resource use/needs associated with the protocols.

For KQ2, in addition to protocol characteristics, we extracted details on study design (RCT, concurrent non-randomized comparison, pre-post comparison), the setting and population it was implemented in (eg, hospital and patient characteristically, and patient, staff, and process outcomes (including seclusion and restraint events). Data extraction was conducted by 1 reviewer and confirmed by a second reviewer. Disagreements were resolved by consensus or discussion with a third reviewer.

Study risk of bias was independently assessed by 1 senior reviewer using questions derived from the Cochrane Risk of Bias and the ROBINS-I (Risk Of Bias In Non-randomized Studies - of Interventions) tools (Appendix C).^36,37^ For all study designs, we additionally evaluated whether the article was free of discrepancies and reporting of patient eligibility criteria, protocols, setting, and outcome assessments were sufficiently clear. For RCTs, we also evaluated methods of randomization, allocation concealment, and whether staff were blinded. For NRCSs (with concurrent or pre-intervention controls), we evaluated selection of patients, characteristics of comparison ward, and strategies to deal with confounders.

## SYNTHESIS AND CERTAINTY OF EVIDENCE

Due to extensive variability in settings, interventions, and measured outcomes, we synthesized results qualitatively. For KQ1, we described the characteristics of protocols, as well as factors associated with their design (eg, organization, intended setting) and potential implementation (eg, resource and staffing needs, where reported).

For KQ2, in addition to the information described for KQ1 about the protocols, we describe their design and their implementation. Additionally, we assessed the strength of evidence following the GRADE (Grading of Recommendations Assessment, Development and Evaluation) approach for determining conclusions and certainty of evidence.^38^ We compiled key study findings in evidence profiles, which provide the basis for determination of certainty of evidence and summarize conclusions for prioritized outcomes. Within each priority outcome, we considered the study design, the number of studies (and participants), methodological limitations (ie, risk of bias), directness of the evidence, precision of the findings, consistency across studies, and other issues. Based on these, we determined certainty of evidence, which could be high, moderate, or low. Where we found extremely limited evidence, we report that there is insufficient evidence to draw conclusions. We report our summary of findings for each outcome, within comparable protocol groups.