# INTRODUCTION

## PURPOSE

The Veterans Affairs (VA) Evidence Synthesis Program (ESP) was asked by the VA Office of Mental Health and Suicide Prevention (OMHSP) for an evidence review on protocols to reduce seclusion practices for adults ≥18 years of age hospitalized in inpatient mental health units. Previous systematic reviews have found limited benefits of seclusion, raising ethical concerns with the continued use of these practices. A 2017 report commissioned by the Joint Commission found that VA hospitals use more seclusion than non-VA hospitals. In response to the Joint Commission report, OMHSP developed a seclusion and restraint reduction toolkit, which was credited with a voluntary reduction in seclusion practices within the VA. OMHSP is in the process of updating the national Inpatient Mental Health Directive. This evidence review will inform the Inpatient Mental Health Directive and determine whether some level of seclusion practices provide benefit or if the harms merit a complete ban, relative to alternative practices.

## BACKGROUND

In psychiatric inpatient settings, conflict behaviors such as patient aggression, agitation, self-harm, and other potentially dangerous behaviors require immediate intervention to prevent physical and emotional injury to the patient, other patients, and staff.^1^ Conflict behaviors also contribute to staff stress and burnout.^2,3^ There are limited data on the incidence of challenging or dangerous behaviors in inpatient settings, with estimates varying from 8% to 76%.^4^ The large variation in estimates is, in part, due to ambiguous definitions of these behaviors and lack of processes for standardized reporting.^4,5^ Managing aggression, agitation, and other potentially dangerous behaviors is challenging because it requires balancing the autonomy and safety needs of the patient with other individuals who may be impacted by the patient.^6^

Seclusion is 1 type of intervention that is used to manage conflict behaviors that place patients and staff at risk of immediate harm.^7^ Although definitions in the literature vary, seclusion generally is recognized as involuntarily confining a patient alone in a locked room or restricted area until the patient’s conflict behaviors subside.^8^ How seclusion is implemented can vary significantly across settings. For example, the characteristics of the restricted area can vary (eg, furnished or unfurnished room), and seclusion may or may not be combined with other involuntary interventions such as physical restraints or pharmacological methods.^9^

There are few randomized controlled trials (RCTs) examining the benefits and harms of seclusion.^10–13^ There is widespread ethical concern that seclusion is a coercive^a^ practice that violates patients’ rights and autonomy and some evidence that patients prefer forced medication over seclusion.^9,14–16^ Staff also have negative perceptions of seclusion.^17^ In addition, epidemiologic and quasi-experimental studies have found that seclusion may cause harms to patients including exacerbation of post-traumatic stress symptoms, emotional distress, negative attitudes toward psychiatric treatment,^18^ and increased length of stay.^11,19–22^ Furthermore, the practical act of placing patients in seclusion may expose staff to additional risk of injury and can cause staff to experience emotional distress.^23,24^

In 2008, the Joint Commission established the Hospital-Based Inpatient Psychiatric Services (HBIPS) measure set which includes hours of seclusion per 1,000 patient hours as a quality measure.^25^ Data from hospitals reporting HBIPS show large variation in the use of seclusion across the United States (US).^26,27^ For example, in 2014, psychiatric facilities in the US reported using seclusion for an average 0.3 (standard deviation [SD] 0.8) per 1,000 patient hours with a wide interquartile range (0.02 to 0.22).^26^ When these data were stratified by hospital type, for-profit psychiatric hospitals used seclusion for the least amount of patient hours (mean 0.1 [SD 0.7], interquartile range: 0.002 to 0.1) and VA hospitals used it the most (mean 0.4 [SD 0.8], interquartile range: 0.0 to 0.3). It is important to note that these estimates do not account for patient case-mix, which may vary substantially across settings (leading to more or less aggressive or agitated behaviors potentially requiring seclusion). Less is known about the practical implementation of seclusion practices (eg, space and personnel resources associated with its use, or context-specific factors that may lead to greater or lesser use).

Over time, seclusion has increasingly been viewed as an intervention of last resort and there are multiple policy initiatives to reduce seclusion.^27–30^ This includes the Veterans Health Administration (VHA) Handbook 1160.06, which states that “seclusion and restraint are interventions of last resort” and directs clinicians in inpatient units to explore ways to prevent, reduce, and eliminate seclusion.^30^ However, reducing clinicians’ use of seclusion requires safe and effective alternative intervention(s) to replace seclusion. Safewards is an example of a protocol to reduce seclusion and consists of a package of intervention strategies that target conflict-originating factors, flashpoints that indicate imminent conflict behaviors, and the link between flashpoints and conflict behaviors.^31^ Examples of Safewards interventions include mutually agreed upon standards of behavior by and for staff, short advisory statements on handling flashpoints, distraction and sensory modulation tools to use with agitated patients, displays of positive messages around the ward for patients, and implementation of de-escalation plans.

Multiple inpatient unit-level policies, which we define in this review as protocols, have been devised to help reduce challenging patient behaviors that precede seclusion in an effort to reduce seclusion itself or help staff manage challenging patient behaviors when they occur; yet the effect of protocols on patient and staff outcomes and the resource needs required to implement these protocols remain unclear.^11–13,32^ We therefore conducted a systematic review on protocols to reduce seclusion for adult patients in inpatient mental health units. In this report, we describe protocols and synthesize the evidence of the effects of the protocols in terms of high-priority clinical outcomes, resource utilization, and staff outcomes to help guide decision-making.

a We use the term “coercion” in this report without judgment or intention of implying clinician stigma. Rather, we use this term to be consistent with our observations of how the literature describes a group of measures that may be applied “against the patient’s will or in spite of his or her opposition” (such as seclusion, restraint, and forced medication) to manage patient care (Chieze 2021). If a study reported coercion as a composite outcome in their results (ie, a combined outcome of seclusion and other coercive measures), we report the study definition of coercion. If the study did not report the definition of coercion, we indicate it was not reported.