# APPENDIX K PEER REVIEW DISPOSITION

Comment # | Reviewer # | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | 1 | Yes | Thank you.
2 | 2 | Yes | Thank you.
3 | 3 | Yes | Thank you.
4 | 4 | Yes | Thank you.
5 | 5 | Yes | Thank you.
6 | 7 | Yes | Thank you.
Is there any indication of bias in our synthesis of the evidence?
7 | 1 | No | Thank you.
8 | 2 | No | Thank you.
9 | 3 | No | Thank you.
10 | 4 | No | Thank you.
11 | 5 | No | Thank you.
12 | 7 | Yes - Themes of self-report data as biased and RCTs as the only way to conduct research on IMH units is not realistic. It seems the authors do not have a clear understanding of the context of VHA IMH services. | Thank you for this comment although we disagree with the assertion that the synthesis is biased. Our careful attention to the methods of included studies and contextualizing findings based of these methods, represents the absence (rather than presence) of bias in the synthesis.; We appreciate the challenges of conducting a randomized trial in inpatient mental health units, but note several included studies used this method. The results and discussion sections raise attention of readers to potential for deviations from what may be the causal relationship between the interventions and outcomes based on established epidemiological methods.; While self-report data can be informative, they also hold the potential for bias due to lack of control and potential for self-observers to collect incorrect or biased assessments (especially if they are aware of the hypothesis of the study and ideal outcomes to be obtained), and therefore it is important to interpret self-report data with caution. Self-report data could provide useful information that can be integrated into development of new programs or for more rigorous controlled trials.
Are there any published or unpublished studies that we may have overlooked?
13 | 1 | No | Thank you.
14 | 2 | No | Thank you.
15 | 3 | No | Thank you.
16 | 4 | No | Thank you.
17 | 5 | No | Thank you.
18 | 7 | Yes - VHA uses PMDB as its primary intervention to prevent disruptive behavior. Nurse/staffing training related to therapeutic communication are also important in preventing disruptive behaviors. Those topics were not examined in this review. | The reviewer comment suggests we missed a program and not a study meeting the review eligibility criteria, specifically. The PMDB is required training at the VA but it is not inpatient specific. Additionally, we searched for studies of this program and have found only one (https://cdn.mdedge.com/files/s3fs-public/Document/September-2017/022080016.pdf). This study does not mention seclusion as a goal for the program (thus not meeting our definition of an eligible intervention) or report seclusion as an outcome. We therefore do not believe we have missed a study of the PMDB program.
Additional suggestions or comments can be provided below.
19 | 1 | None | Thank you.
20 | 2 | Page 17, line 20: statement of “there are limited data on the benefits on seclusion.” The focus of the report is on the effective strategies of reducing seclusion events and not examining the benefits of seclusion itself which would be a different focus of the report. | This was an error as it was meant to say there are limited data on the benefit of protocols to reduce seclusion. We have corrected it to read as follows: “Despite great interest from policymakers, providers and patients for effective alternatives to seclusion, there are limited data on the benefits of protocols designed to reduce seclusion in adult inpatient mental health wards”
21 | 3 | When reading this overview - I have questions regarding patient population types in the reviewed publications. We are looking at effective ways to reduce seclusion in practice - but there is no layering if there were more effective approaches with certain age groups, sexes, or admitting diagnoses. Is there any information/data on when event occurred in relation to time after admission. We would need to consider the acuteness of the psychiatric situation with the patient and the correlation to restraint/seclusion in relation to that. Do certain admitting diagnoses result in higher occurrences of these events? That would help drive possible interventions based upon that unique factor. Interventions to reduce the number or length of seclusion events is great information - but in what context and relation to the majority percentage of patient situations. The information is great and demonstrates the need for more in depth research with set parameters for evaluation - but it led to many more questions about demographics, diagnoses, and acuity. Another factor is the type of inpatient setting - is it a mixed milieu? How can we bucket results based upon similar settings? | We appreciate the reviewer’s comment that layering of factors that could reasonably impact/change results is important to consider and would be helpful in guiding policy and recommendations. Unfortunately, a major limitation of the studies included in this review (called out in our report) is the lack of reporting of patient data and specific analyses taking patient data into consideration. Diagnosis were reported in only 9 studies, and no study reported subgroup analyses by patient demographics or acuity. The interventions were complex and involved tailoring strategies based on individual patient context, but results were reported at aggregate for all patients. The Discussion notes that future studies should make greater efforts to study effect modification based on demographics, diagnoses, or acuity.
22 | 4 | pg. 13 line 10:“...studies excluded, incarcerated, while incarcerated is excluded, many patients on inpatient have criminal records e.g., assault | Thank you for this comment. We agree that some patients in included studies may have criminal records. In consultation with experts during the scoping process we exclude studies with incarcerated populations because the management of patients in a forensic unit may be different than a non-forensic inpatient mental health unit. We have added text to the Methods section to clarify the inclusion criteria: “For both KQ 1 and KQ 2, studies were excluded if they included incarcerated or institutionalized populations as these settings were deemed to be outside the scope of interest to our stakeholders.”
23 | 4 | pg. 17 line 17: “...other coercive measures” again consider removing this staff stigmatizing language | In the Introduction we have added a clarification about the term coercion. The footnote reads: “A note on the use of the term ‘coercion’ this report. We use the term coercion without judgement or intention of implying clinician stigma. Rather, we use this term to be consistent with our observations of how the literature describes a group of measures that may be applied “against the patient’s will or in spite of his or her opposition” (such as seclusion, restraint and forced medication) to manage patient care.(Chieze, 2021) If a study reported coercion as a composite outcome in their results (i.e., a combined outcome of seclusion and other coercive measures) we report the study definition of coercion, where possible.”
24 | 4 | pg. 18 line 9: restructure units to include open wards and sensory/comfort wards” VA does not use “open wards” patients may be on a voluntary or involuntary commitment-the latter typically associated with lack of insight into illness and need for tx. | Per our protocol (based on expert input) we included studies or interventions conducted in high income countries that evaluated environmental restructuring. Some environmental restructuring studies evaluated open door policies. We revised the text in this section to note that open doors were only considered in some of the hospital restructuring studies, among other architecturally positive or service reorganization elements. The decision to make a ward open depends on type of patient population. We also note that open door policies may not be relevant to the VA.
25 | 4 | pg. 19 line 17:“coersive practices”, this terminology is very controversial and may denote a negative connotation despite staff doing everything to prevent seclusion, staff are doing something unethical-suggest not using this term throughout this report. | Please see our reply to comment 23.
26 | 4 | pg. 19, line 42: seclusion definition-use TJC and code of fed regs definition. | In the Introduction (pg. 19 line 42) we describe seclusion following the approach used in the literature.
27 | 4 | pg. 19 line 47: “...seclusion may/may not be monitored”-this is not accurate, TJC requires all patients in seclusion to be monitored. | In the Introduction we note that how seclusion is implemented in practice varies. We revised the statement to no longer emphasize as an example that in practice patients in seclusion may or may not be monitored. with
28 | 4 | pg. 21 line 9: “we worked with representatives from OMHSP...please add ONS (Office of Nursing Services) which I fall under. | We revised the text to acknowledge the affiliation of the Operations Partners and TEP. The Preface also lists all TEP members, their titles, and affiliations.
29 | 4 | pg. 23, line 8: inclusion criteria: population consists of state statues of voluntary/involuntary commitments | We revised the inclusion criteria to note the patient population consists of Adults with psychiatric conditions admitted (voluntary / involuntary) and being treated in hospital inpatient units.
30 | 4 | pg 24, line 30: “staffing” there is no mention of staffing ratios and staffing mix (particularly) RNs and impact on seclusion (ANA position statement: Reduction of Patient R&S in Healthcare Settings. | Thank you. The word ‘mix’ was missed from KQ 2 and has been added.
31 | 4 | pg. 36 line 55: “light and noise levels” no mention of the temperature in the unit. | Light and noise was mentioned as it was a specific example of environmental restructuring in one of the protocols listed. While unit temperature could feasibly be considered (as part of the environment or sensory modulation rooms), it was not mentioned explicitly and is not reported here.
32 | 4 | pg. 63 line 23: “bright light” could be overstimulating-would consider “natural lighting” per the Design Guide. | We have changed bright light to natural light.
33 | 4 | pg. 69 line 16: “restructure units to include open unit” again this is not the policy or practice in VA an not a reasonable consideration. Would also offer that other patient care needs are considered and addressed (trauma informed care; pain; withdrawal; hunger, thirst; disturbing hallucinations; intrusive thoughts) as well as unit management philosophy /attitudes of staff (recovery care vs. custodial care). in addition to staff education levels (RNs-ADN, BSN, MSN, certifications etc) and staff ratio and mix (e.g. All RN staff and impact on reducing seclusion). | Please see reply to comment 24.
34 | 5 | Minor edits listed below with page/line reference. One suggestion: Clarify early what is included in “coercion events” ... restraint, seclusion, meds, all of the above, something else. There is a lot about “composite measures for coercion” (also not well defined) and it’s not clear what elements would be included in those composite measures until page 15 and then only by inference in line 7. | We revised the Introduction to clarify the meaning of coercion (see footnote a). When studies define coercion or composite measures we report the definition. Where studies do not define coercion, we indicate that the definition is not reported.
35 | 5 | Edit Suggestions:; Page 12 Line 29 “reduce seclusion on patient and staff outcomes and the resource needs required to implemented” [change to implement] | Thank you, this change has been made.
36 | 5 | Page 13 Line 35 “seclusion, respectively.. Based on our coding of the interventions, we identified 5 intervention” [remove extra period] | Thank you, this change has been made.
37 | 5 | Page 14 Line 43 “for some outcomes and spares reporting of data. Studies provide insufficient evidence (providing” [change spares to sparse] | Thank you, this change has been made.
38 | 5 | Page 16 Line 19–20 “Despite great interest from policymakers, providers and patients for effective alternatives to seclusion, there are limited data on the benefits of seclusion.” [Is there a word missing here? Because not sure what this introduction to the discussion means (how the interest in alternatives relates to the benefits of seclusion) or how it ties into the paragraph that follows] | This was an error. We have corrected it to read as follows: “Despite great interest from policymakers, providers and patients for effective alternatives to seclusion, there are limited data on the benefits of protocols designed to reduce seclusion in adult inpatient mental health wards”
39 | 5 | Page 16 Line 44 “Outcomes such as of patient aggression, patient/staff injuries, and patient/staff” [remove “of”] | Thank you, this change has been made.
40 | 5 | Page 17 Line 51 “that aim implement all or parts of these interventions.” [add “to” after aim] | Thank you, this change has been made.
41 | 5 | Page 22 Line 30 “organizations in US or Canada or implemented or intended to be implemented these countries.” [add “in” after intended to be implemented] | Thank you, this change has been made.
42 | 5 | Page 37 Line 56 “2) advisory statements to handled flashpoints;” [change handled to handle] | Thank you, this change has been made.
43 | 5 | Page 65 Line 36 “reduce the likelihood of a precipitating behavior requiring seclusion or any alternatives.” [I think the “a” needs to be removed to say “reduce the likelihood of precipitating behavior requiring seclusion or any alternatives”] | Thank you, this change has been made.
44 | 5 | Page 65 Line 59 “restrain was unknown due to insufficient evidence” [should be “restraint” rather than restrain] | Thank you, this change has been made.
45 | 7 | Thank you for reviewing efforts to reduce seclusion on IMH units. The following are comments provided to enhance the draft. P11. Line 21. “open-door policy” is confusing as VHA inpatient mental health units are locked. Does this mean internal doors on the unit? Or did your review include literature on non-VA voluntary private pay facilities? VA provides IMH care to a very different clinical population than those treated in private pay free-standing IMH units. | Please see reply to comment 24 above
46 | 7 | P11. e23. The “ie,” here is confusing. Perhaps a word is missing? This occurs again on line 53. This phrase: environment restructuring intervention function, or intervention function environment restructuring, is not used in the clinical IMH setting in VHA. Thus, providing an operational definition for the reader would be important. Perhaps deleting the word “function” may help make this term more understandable to the reader. | We extracted protocol elements into 1 of 9 intervention functions defined by the behavior change wheel. “Environmental restructuring” represents 1 of the 9 intervention functions. We revised the text in the Executive Summary clarify our intent.
47 | 7 | In the summary, it would have been helpful to describe more clearly interventions that focused on staff v. interventions focused on patients. The first paragraph of the discussion explained this better. | We have called out the target of the intervention functions (staff vs. patient vs. both) more explicitly in the Executive Summary
48 | 7 | P 11 Line 47. Use of the term coercion is problematic as it has a negative connotation. Recommend stating that this term is what was used in the research you reviewed. Coercion implies that staff are threatening or forcing patients to do something they don’t want to do. That is not acceptable clinical care. Coercion is different from implementing seclusion or restraint for patient and staff safety purposes. VA must follow TJC requirements. Excerpt from TJC; PC.03.05.01:; Program: Hospital; Chapter: Provision of Care, Treatment, and Services; Introduction: N/A; Rationale: N/A; Elements of Performance:; 1. The hospital uses restraint or seclusion only to protect the immediate physical safety of the patient, staff, or others.; 2. The hospital does not use restraint or seclusion as a means of coercion, discipline, convenience, or staff retaliation.; 3. The hospital uses restraint or seclusion only when less restrictive interventions are ineffective.; 4. The hospital uses the least restrictive form of restraint or seclusion that protects the physical safety of the patient, staff, or others.; 5. The hospital discontinues restraint or seclusion at the earliest possible time, regardless of the scheduled expiration of the order. Please find a different term to use in this paper. | See reply to comment 23 above.
49 | 7 | P. 12 Line 21. Physical restraint is actually the intervention of last resort, as it requires VHA staff to actually put hands on the patient to prevent movement. Seclusion is the least restrictive type of restraint. However, external accreditation standards (e.g., TJC) results in seclusion being more staff-intensive (seclusion requires direct observation) as compared to restraint. That should be clarified here. | We revised the text to emphasized that that seclusion is increasingly seen as “an” intervention of last resort (i.e.., one of several, including restraint), not “the” intervention of last resort. For that reason, we have kept the sentence as is as we believe the intent is clear.
50 | 7 | P. 13 Line 14. Operationally define behavioral change wheel. | We have added additional details on the behavior change wheel (already in the full report) in the Execute Summary.
51 | 7 | P. 13 Line 52. In terms of discussing reduction of seclusion from transforming a unit from a locked inpatient unit to a residential unit, that is essentially changing the level of care from inpatient to residential, which are not comparable. We have locked units that treat patients who are committed (either voluntarily or but the state court) to receive acute inpatient mental health care. A residential program is not acute care. | See reply to comment 24 above.
52 | 7 | P. 14 Line 35. Unclear the operational definition of enablement. | The operational definition of enablement (along with the operational definition of the other 8 intervention functions) was not included Executive Summary as this would make the summary too cumbersome. The details of how each intervention function was defined is included in the full report and Appendix B.
53 | 7 | P15 Line 38. Should “creates” be “crates?” | Thank you, this change has been made.
54 | 7 | P. 17 Line 12. Again, “open” wards is a residential level of care which is different from IMH care. This summary seems like a suggestion to make acute inpatient units unlocked wards, which is not realistic. Patients who do not need acute inpatient care would be discharged to a lower level of care such as residential or outpatient mental health services. This comes up again on P. 18 Line 9. | See reply to comment 24 above.
55 | 7 | P. 33 Line 49. Unclear how continuous video monitoring is described as a restriction. Monitoring patients when they are using items that can be used for self-harm or harm to others is a safety procedure. Similarly, unclear how requiring patients to sign an agreement (BTW unsure what the agreement is about) prior to using the sensory modulation rooms is a restriction. | The restriction intervention function is defined as the use of rules to reduce the opportunity to engage in the target behavior or competing behaviors (see Appendix B). In one study, patients were informed that they may use the space as long as they were safe, but they would be monitored on video and staff could enter the space (ie, they would lose the privilege of using the room) if they were displaying unsafe behavior. In another study, patients had to sign an agreement form to use the sensory modulation room. Those who were unable/unwilling to sign the agreement form were not allowed to use the sensory modulation room. We interpreted both cases as examples of rules put in place to encourage positive and safe behavior for patients. We have added a clarifying statement to the agreement form (“...patients who were unable or unwilling to sign the agreement form were not allowed to use the sensory modulation room”).
56 | 7 | P. 33 Line 53. Also unclear how customizing a sensory modulation room is enablement. Does enablement = customization? Not sure what to make of this as a treatment plan, for example, should be customized to the individual. So is all treatment enablement? | The enablement intervention function is defined as increasing means/reducing barriers to increase capability or opportunity. We interpreted the extra efforts made by protocols to tailor the rooms to the specific requests of patients on the ward at that present moment (based on intake forms) and supports put in place for patients to voluntarily use the rooms as examples of increasing patients’ psychological capability and reducing patients’ social and physical barriers (ward culture and set up) to use the sensory modulation rooms.
57 | 7 | P. 49. Risk Assessment. As I read through this, I think what is missing for me is that it is unrealistic to expect any changes in rates of seclusion and restraint simply based on risk assessment. What is key is what you DO with the risk assessment data. In other words, how is the risk assessment date utilized by staff. It is not simply conducting a risk assessment that is key. It’s that treatment is customized base on risk assessment results. Additionally, it seems that this section focused on risk of violence. On IMH assessing risk for self-harm is equally important, if not more so, in reducing seclusion and restraint. It seems that got lost in this review. | We describe the risk assessment protocols as they are reported in the studies. We agree that the staff action in response to the risk assessment is key, although not all protocols were explicit with this in their descriptions of the intervention. Where studies reported subsequent management protocols (informed by the risk assessments) we captured this information and coded the appropriate intervention functions. We have revised the name for this group of studies to be “risk assessment and management protocols”.
58 | 7 | A major theme throughout the report is that self-report data is biased, which is interesting. It seems the assumption is that the best methodology for research on variables related to reducing seclusion and restraint can only be found in RCTs. There seems to be a lack of understanding of how having researcher observers on a unit might impact staff and patient behavior, not to mention to difficulty in accommodating such a presence on many inpatient units where space is a premium. Where would the observers be situated? Some units have not had episodes of seclusion or restraint for years—how is that coded? No suggestions are provided on how to better conduct applied research in this type of setting. | It is important to distinguish that bias from self-report data and non-RCT designs are different concepts. Self-reported outcomes (which are subjective and thus prone to performance bias) can still be used in RCTs. All studies in the review used self-reported data.; Only 4 studies used an RCT design (which controls for factors associated with outcomes besides the intervention to give a more valid inference of treatment effect). We present the findings in the context of these potential biases so that decision-makers can have the full picture to inform their recommendations. We acknowledge the challenges with implementing more robust, unbiased methods in our discussion and provide suggestions for future research.
59 | 7 | P. 67 Line 50. “Recommendations” should be replaced with “requirements.” Policies do not recommend behaviors rather, they stipulate required services. This occurs again on Line 58. | Thank you, this change has been made.
60 | 7 | P. 68 Line 8. Again, there seems to be a lack of understanding that an open ward is not consistent with an acute inpatient level of care. An open ward is essentially residential care. This must be removed. | See reply to comment 24 above.
61 | 7 | P. 68 Line 10. Unclear why there is emphasis on smaller units. There was nothing in this report that looked at size of unit (square footage), number of beds per room, and related that to rates of seclusion and restraint. Indeed, having more treatment space and space for patients to interact, along with well-designed layouts with natural light and effective acoustics management is important. But that is not what this paragraph states. | Our intent in listing unit size as a feature to consider for future wards was not about square footage but about how many patients are housed in a unit - which was based on evidence we found in the hospital restructuring studies. We have modified this statement to add this clarification and added additional details noted by the reviewer which is consistent with the evidence we found. The sentence now reads: “As VA constructs new facilities it should consider constructing smaller units (ie, number of patients) with well-designed layouts incorporating natural light, effective acoustics management, and green space”.
62 | 7 | P. 68 Line 16. With the implementation of Cerner efforts to standardize documentation of seclusion and restraint may be proceeding more rapidly. FYI many facilities do conduct risk assessment (the Violence Risk Assessment Instrument was developed in VA) and certainly are required to conduct self-harm risk assessment. This section read as if VA does not currently do that. | Thank you for this comment. We agree that some efforts to standardize are underway. We have added “VA-wide improvement efforts have already been implemented towards standardized documentation in the electronic health record, such as the Violence Risk Assessment, however further opportunities exist which can include standardizing measures in the electronic medical record to document process (eg, use of seclusion) and outcomes (eg, aggression).”
63 | 7 | A few typos here and there like extra periods, inserting a word out of place, wrong spelling of word, etc.. | Thank you. We have reviewed the report for typographical errors and made the necessary corrections.