# APPENDIX J RESULTS

## Results Summary: Seclusion

Author, Year, Country, Design | Intervention Label, Sample Size | Comparator Label, Sample Size | Episodes of Seclusion | Time in Seclusion
Hospital/Unit Restructuring
Hochstrasser, 2018, Switzerland, Pre-post | Open-door policy with recovery-oriented care; 14,435 patients (may include some admissions before policy which was implemented in Aug 2011); 2,803 patients in 2015 | Pre-intervention (practice as usual); 2,924 patients in 2010 | Seclusion; OR (95% CI) open door policy: 0.88 (0.83 to 0.92); Cases with at least 1 seclusion; Last year of post intervention follow-up (2015): 3.5% (97/2803); Baseline year (2010): 8.2% (239/2924); Mean (SD) number of seclusion; Last year of post intervention follow-up (2015): 2.9 (3.4); Baseline year (2010): 5.1 (8.7) | Mean (SD) hours of seclusion; Last year of post intervention follow up (2015): 18.2 (6.5); Baseline year (2010): 27.1 (16.4); One-way ANOVA p <0.001
Hunter, 1993, United States, Pre-post | After hospital restructuring; 78 patients | Before hospital restructuring; 66 patients | No. seclusion events post (10 months) vs pre (10 months); Post period no. events: 32; Pre period no. events: 31; Difference: p = NS | Hours of seclusion episode; Post period mean (SD): 2.3 (2.8); Pre period mean (SD): 5.0 (8.4); Difference: p = 0.02
Jenkins, 2014, United Kingdom, Pre-post | Purpose built psychiatric intensive care unit; 18 patients | Old unit; 18 patients | No. seclusion incidents post (3–6 months) vs pre (3–6 months); Post period no. events: 3; Pre period no. events: 14; Difference: p = 0.001 | Total duration seclusion (minutes); Post period: 531; Pre period: 2117; Difference: p = 0.001; Mean (SD) duration of seclusion (minutes); Post period: 190 (122); Pre period:153 (98); Difference: p = 0.288
Rohe, 2017, Germany, Pre-post | Architecturally positive redesign | Pre-intervention (practice as usual) | NR | NR
Staff Education/Training
Bowers, 2008, United Kingdom, Concurrent and pre-post | City Nurse Intervention - Escalation Training; 3 wards | Pre-intervention (practice as usual) and concurrent control (practice as usual); 5 wards | Seclusion per shift (pre-post analysis only); Post period mean (SD): 0.007 (0.098); Pre period mean (SD): 0.016 (0.125); Difference (among only intervention ward): p = 0.019
Forster, 1999, United States, Pre-post | Staff training | Pre-intervention (practice as usual) | NR | NR
Haefner, 2021, United States, Pre-post | De-escalation training (TeamSTEPPS) | Pre-intervention (practice as usual) | Seclusion events post (2 months) vs pre (2 months); Post period no. events and rate: 15 (4.4%); Pre period no. events and rate: 23 (5.9%); Difference: p = 0.349
Sensory Modulation
Lloyd, 2013, Australia, Concurrent | Sensory modulation room; NR | Concurrent control (practice as usual); NR | Seclusion episodes pre (6 months) and post (6 months); [underlined: Intervention ward]; No. events (post): 53; No. events (pre): 157; [underlined: Comparator ward]; No. events (post): 81; No. events (pre): 46; Significant decrease in rate of seclusion for intervention vs comparison ward (p <0.001) | Duration of seclusion; “No evidence that the duration of seclusion episodes changed.”
Cummings, 2010, United States, Concurrent | Comfort room | Concurrent control (practice as usual); Pre-intervention (practice as usual) | NR | NR
Azuela, 2018, New Zealand, Pre-post | Sensory modulation room; N NR | Pre-intervention (practice as usual); N NR | Seclusion episodes post (1 year) vs pre (1 year); Comfort room was implemented in both Unit A and B; results were analyzed separately as pre-post; Unit A total events (post): 81; Unit A total events (pre): 91; Unit A Median (SD) (post): 6.5 (3.4); Unit A Median (SD) (pre): 8.5 (3.9); p>0.05; Unit B total events (post): 115; Unit B total events (pre): 162; Unit B Median (post): 7.5 (6.2); Unit B Median (pre): 14.5 (3.6); p = 0.04 | Seclusion duration post (1 year) vs pre (1 year); Unit A Median (SD) hours (post): 68.75 (77.512); Unit A Median (SD) hours (pre): 126.80 (133.97); p>0.05; Unit B Median (SD) hours (post): 145.30 (196.8); Unit B Median (SD) hours baseline (pre): 360.30 (220.12); p = 0.02
Novak, 2012, Australia, Pre-post | Sensory room; 75 patients^36^ | Pre-intervention (practice as usual); 75 patients | Seclusion episodes post (12 months) and pre (12 months); Post period mean (SD): 18.2 (7.7); Pre period mean (SD): 17.2 (6.0); Difference: p = NS | NR
Sivak, 2012, United States, Pre-post | Comfort room; NR | Pre-intervention (practice as usual); NR | Seclusion episodes post (4 months) vs pre (4 months); Pre intervention mean rate of seclusion/1000 days of client care before intervention (July through Oct 2010): 0; “Since the initiation of the comfort rooms, there has been no use of seclusion or restraint”
Smith, 2013, United Kingdom, Pre-post | Sensory room; NR | Pre-intervention (practice as usual); NR | No. seclusion events post (3 months) vs pre (3 months); Post period no. events: 37 (25 were repeat events by 6 patients); Pre period no. events: 27 (12 were repeat events by 4 patients; Difference: NS; Authors notes “If the repeater seclusion were extracted as anomalies, the rates of seclusion would be seen to have been reduced.” | Seclusion duration post (3 months) vs pre (3 months); Post range: 45 minutes to 16 hours 30 minutes; Pre range: 40 minutes to 3 days; Difference: NR; Mean (SD) duration of seclusion (minutes) post (3 months) vs pre (3 months); Post period: 3 hours 59 minutes (3 hours 40 minutes); Pre period: 7 hours 30 minutes (17 hours 25 minutes); Difference: NR; “This may look as if the mean duration of time in seclusion decreased considerably after the sensory room had been introduced. However these results are skewed by some extreme values of very long seclusion time periods, with two long seclusion episodes in [the pre period] of 2 days, 6 hours and 3 days, and in [the post period], there was one seclusion episode of 16 hours 30 minutes. With these three outliers removed from the data set, the mean duration in [the pre period] (n = 25) was 2 hours 46 minutes (Sd = 2 hours 50 minutes) and in [the post period] (n = 36) it was 3 hours 37 minutes (SD = 3 hours 7 minutes). Therefore the average length of time in seclusion had actually increased, not decreased following the introduction of the sensory room.”
Zimmermann, 2020, United States, Pre-post | Serenity room | Pre-intervention (practice as usual) | NR | NR
Risk Assessment
Abderhalden, 2008, Switzerland, RCT | Structured risk assessment (BVC) | Control (practice as usual) | NR | NR
van de Sande, 2011, Netherlands, RCT | Structured risk assessment (BVC); 20 beds and 207 patients during intervention period | Control (practice as usual); 16 beds in control wards and 251 patients during intervention period | Seclusion incidents; 30-week intervention RR (95% CI): 1.01 (0.74 to 1.88); 10-week baseline RR (95% CI): 1.19 (0.76 to 1.88); % change in baseline risk ratio to intervention period risk ratio: −15%; (p = NS); No. secluded patients; 30 week intervention RR (95% CI): 1.71 (1.12 to 2.67); 10 week baseline RR (95% CI): 1.42 (0.83 to 2.48); % change in risk ratio of no. of patients exposed to seclusion to risk ratio in intervention period: 8%; (p = NS) | Hours in seclusion; 30-week intervention RR (95% CI): 0.62 (0.58 to 0.88); 10-week baseline RR (95% CI): 1.12 (1.01 to 1.19); % change in risk ratio in baseline to intervention period: −45% (p <0.05)
Blair, 2017, United States, Pre-pos | Structured risk assessment (BVC); 8,029 admissions | Pre-intervention (practice as usual); 3,884 admissions | Seclusion episodes post (12 months) vs pre (12 months); Proportion of patients secluded (post): 4.4% (213/8,029 admission); Proportion of patients secluded (pre): 9.2% (358/3884 admission).; Difference (12 months post intervention): −52% (p <0.001) | Duration of seclusion per admission post (12 months) vs pre (12 months); Difference (12 months post intervention): −27% (p = NR); Duration of seclusion per admission in 12 months before intervention: NR; Minutes in seclusion post (12 months) vs pre (12 months); Mean (SD) (post): 516.2; Mean (SD) (pre): 337.7 (NR); Difference: p <0.01
Clarke, 2010, Canada, Pre-post | Structured risk assessment (BVC); N NR | Pre-intervention (practice as usual); N NR | Episodes of seclusion; 2 months after intervention: 22 episodes/month; 3 months intervention phase: 12 episodes/month; 2 months before intervention: 30 episodes/month; p = NR
Harrington, 2019, Australia, Pre-post | Risk assessment (Clinical Risk Management Initiative); 965 admissions post-implementation | Pre-intervention (practice as usual); 1,090 admissions in pre period | Seclusion per 1,000 occupied bed days post (18 months) vs pre (24 months); Difference in rates (95% CI): −12.8 (−17.2 to −8.43); Pre-Intervention rate (95% CI): 43.7 40.6 to 46.9); RR (95% CI): 0.71 (0.63 to 0.80; p < 0.001)
Manning, 2022, United States, Pre-post | Risk assessment (modified Agitation Severity Scale); 389 patients | Pre-intervention (practice as usual); 353 patients | Seclusion incidents post (18 months) vs pre (18 months); Post: 28; Pre: 22; Difference: p = NS | Mean (SD) minutes in seclusion post (18 months) vs pre (18 months); Post: 137 (97); Pre: 132 (141); Difference: p = NS
Trauer, 2010, Australia, Pre-post | The Management of Acute Arousal Program; 188 admissions | Pre-intervention (practice as usual); 164 admission | No. seclusion events post (6 months) vs pre (6 months); Post period no. events: 67; Pre period no. events: 64; Difference: 0.51 | Mean (median) duration of seclusion (minutes) post (6 months) vs pre (6 months); Post period: 312 (235); Pre period: 299 (230); Difference: 0.19
Comprehensive/Mixed
Bowers, 2015, United Kingdom, RCT | Safewards | Control wards (physical health program) | NR | NR
Välimäki, 2022, Finland, RCT | Intervention wards; 8 wards, 13 units, 335 nurses, 238 hospital beds, 4,163 patients | Control wards (practice as usual); 7 wards, 15 units, 313 nurses, 235 hospital beds, 4,186 patients | No. seclusion events at ward level/total patients intervention vs control; Baseline n (proportion) intervention: 629/4163 (15.1); Baseline n (proportion) control: 580/4186 (13.9); RR (95% CI) after intervention 0.72 (0.32 to 1.63; p = 0.42); p-value for group * time: 0.003; No. secluded patients at ward level/total patients intervention vs control; Baseline n (proportion) intervention: 342/4163 (8.2); Baseline n (proportion) control: 354/4186 (8.5); RR after intervention (95% CI) 0.76 (0.40 to 1.46; p = 0.41); P-value for group * time: 0.37 | Length per seclusion event on ward level, geometric mean, min intervention vs control; Log-transformed mean difference (95% CI) 0.16 (−0.39 to 0.71; p = 0.56); Baseline geometric mean intervention: 1,378; Baseline geometric mean control: 1,614; p-value for group*time: 0.21
Boumans, 2014, Netherlands, Concurrent | Methodological work approach; 134 patients | Control (practice as usual); 544 patients | Seclusion episodes per 1,000 patient days; [underlined: Change over time in incident of seclusion comparison ward time series]; Coefficient (SE): −0.22 (0.36, p = NS); [underlined: Difference experimental vs comparison ward]; Coefficient (SE): −0.55 (0.20, p <0.01) | Hours in seclusion per 1,000 patient days; [underlined: Change over time in incident of seclusion comparison ward time series]; Coefficient (SE): 0.84 (28.85, p = NS); [underlined: Difference experimental vs comparison ward]; Coefficient (SE): −63.46 (17.25, p <0.01)
Noorthoorn, 2014, Netherlands, Concurrent control | Intervention; 45-bed ward; 768 patients (1,392 admissions) | Control (practice as usual); 38-bed ward; 702 patients (1,138 admissions) | Seclusion episodes; [underlined: Intervention Ward]; No. episode over study period: 39 episodes (30 patients); Seclusion per 1,000 admissions (1st year): 6.7; Seclusion per 1,000 admissions (2nd year): 4.6; Seclusion per 1,000 admissions (3rd half year): 0.7; [underlined: Comparison Ward]; No. episode over study period: 130 episodes (79 patients); Seclusion per 1,000 admissions (1st year): 14.7; Seclusion per 1,000 admissions (2nd year): 21.4; Seclusion per 1,000 admissions (3rd half year): 26.1; Seclusion occurred more in comparison wards: p = 0.001; Hazard ratio for being secluded (comparison ward vs intervention ward): year 1: 2.8 (p = NR), year 2: 5.6 (p = NR) | Seclusion days; [underlined: Intervention Ward]; Seclusion days per 1,000 patient days (2003): 8 days; Number of seclusion days per 1,000 patient days (2004): 3 days; [underlined: Comparison Ward]; Number of seclusion days per 1,000 patient days (2003): 17 days; Number of seclusion days per 1,000 patient days (2004): 19 days; “Duration of seclusions did not differ between wards”
Blair, 2015, United States, Pre-post | Engagement model; NR | Pre-intervention (practice as usual); NR | Annual no. seclusion events post (2002–2013) vs pre (2000); Post no events (2001–2013):; 2013: 13; 2012: 30; 2011: 7; 2010: 3; 2009: 19; 2008: 2; 2007: 0; 2006: 0; 2005: 0; 2004: 1; 2003: 3; 2002: 10; 2001: 53; Pre no events (2000): 101; Difference: NR | NR
Dickens, 2020, Australia, Pre-post | Safewards | Pre-intervention (practice as usual) | NR | NR
Hellerstein, 2007, United States, Pre-post | Comprehensive intervention; NR | Pre-intervention (practice as usual); NR | No. patients secluded month post (67 months) vs pre (20 months); Pre period mean (SD): 3.1 (1.4); Post period mean (SD): 1.0 (1.1); P-value for difference: <0.0001 | Total hours patients secluded month; Pre period mean (SD): 41.6 (52); Post period mean (SD): 2.7 (4.5); P-value for difference: 0.003; % of total patients hours in seclusion; Pre period mean (SD): 0.11 (0.14); Post period mean (SD): 0.007 (0.01); P-value for difference: 0.03
Khadivi, 2004, United States, Pre-post | Comprehensive intervention | Pre-intervention (practice as usual) | NR | NR
Lewis, 2009, United States, Pre-post | Crisis Prevention Management program; NR | Pre-intervention (practice as usual); NR | Episodes of seclusion; “Three of the 4 units had a decrease in the use of seclusion ranging from 30–63%.”
McDonagh (PowerPoint), 2019, United States, Pre-post | Recovery-oriented programming; NR | Pre-intervention (practice as usual); NR | No. episode of seclusion; Post period (3 years): 31; Pre period (3 years): 71; 56.3% decrease (p = NR) | Total hours in seclusion; Post period (3 years): 142; Pre period (3 years): 1205; 88%.3% decrease (p = NR)
Pollard, 2017, United States, Pre-post, Medium | Comprehensive intervention | Pre-intervention (practice as usual) | NR | NR
Richmond, 1996, United States, Pre-post | Comprehensive intervention; NR | Pre-intervention (practice as usual); NR | NR | Hours in Seclusion Post (12 months) vs Pre (12 months); Pre period: 395.55 total seclusion hours; Post period: 788.2 total seclusion hours; 50% increase in seclusion hours
Stoll, 2022, Switzerland, Pre-post | Moral Case Deliberation; NR | Pre-intervention (practice as usual); NR | Proportion of patients secluded; Post period: 9.6% (N = NR); Pre period: 16.7% (N = NR); Difference: p = 0.034; Frequency seclusion episodes among those in seclusion; Post period mean (SD): 3.4 (6.6); Pre period mean (SD): 2.2 (2.5); Difference: p = 0.42 | Time in seclusion; Post period mean (SD): 39.8 (95.2); Pre period mean (SD): 156.2 (268.8); Difference: p = 0.115; Hours seclusion per episode; Post period mean (SD): 10.0 (12.6); Pre period mean (SD): 73.9 (102.3); Difference: p = 0.05
Taxis, 2002, United States, Pre-post | Comprehensive intervention | Pre-intervention (practice as usual) | NR | NR
Whitecross, 2020, Australia, Pre-post | Psychiatric behavior of concern team; 1356 episodes of care | Pre-intervention (practice as usual) | Seclusion episodes per 1,000 occupied bed day post (6 months) vs pre (6 months); Mean 6 months before intervention: 19.2; Difference (6 months post): −65.3%; (p = NR); Proportion of admitted patients secluded post (6 months) vs pre (6 months); Mean 6 months before intervention: 14.7%; Difference (6 months post): −55.7%; (p = NR) | Seclusion hours per 1,000 occupied bed days post (6 months) vs pre (6 months); Mean 6 months after intervention: 76.0; Mean 6 months before intervention: 270.4; Difference (6 months post): −71.9%
Zuehlke, 2016, United States, High, Pre-post | Recovery-oriented program of care | Pre-intervention (practice as usual) | NR | NR

Abbreviations. ANOVA=analysis of variance; no.=number; NR=not reported; NS=not significant; OR=odds ratio; RoB=risk of bias; SD=standard deviation; VA=Veteran Affairs.

## Results Summary: Restraint

Author, Year, Country, Design | Intervention Label, Sample Size | Comparator Label, Sample Size | Episodes of Restraint | Time in Restraint
Hospital/Unit Restructuring
Hochstrasser, 2018, Switzerland, Pre-post | Open-door policy with recovery-oriented care | Pre-intervention (practice as usual) | NR | NR
Hunter, 1993, United States, Pre-post | After hospital restructuring; 78 patients | Before hospital restructuring; 66 patients | No. restraint events post (10 months) vs pre (10 months); Post period no. events: 190; Pre period no. events: 114; Difference: p = NR | Hours of restraint episode; Pre period mean (SD): 11.1 (25.9); Post period mean (SD): 9.2 (9.3); Difference: p = NR
Jenkins, 2014, United Kingdom, Pre-post | Purpose-built psychiatric intensive care unit | Old unit | NR | NR
Rohe, 2017, Germany, Pre-post | Architecturally positive redesign; NR | Pre-intervention (practice as usual); NR | Patients restrained per month and per occupied bed; Post period mean (SE): 0.035 (0.003); Pre period mean (SE): 0.069 (0.004); 50.1% decrease (p <0.001); Days with fixations per month and per occupied bed; Post period mean (SE): 0.081 (0.011); Pre period mean (SE): 0.222 (0.019); 63.3% decrease (p <0.001); Caring restraints per month and per occupied bed; Post period mean (SE): 0.012 (0.002); Pre period mean (SE): 0.024 (0.002); 48.4% decrease (p = 0.001) | Duration (unit NR) of with fixations per month and per occupied bed; Post period mean (SE): 0.962 (0.157); Pre period mean (SE): 2.015 (0.240); 48.4% decrease (p = 0.003)
Staff Education/Training
Bowers, 2008, United Kingdom, Concurrent and pre-post | City Nurse Intervention - Escalation Training; 3 wards | Pre-intervention (practice as usual) and concurrent control (practice as usual); 5 wards | Restraint per shift (pre-post analysis only); Post period mean (SD): 0.031 (0.180); Pre period mean (SD): 0.057 (0.257); Difference (among intervention wards only); p = 0.0172 | NR
Forster, 1999, United States, Pre-post | Staff training; 3,010 admissions | Pre-intervention (practice as usual); 2,560 admissions | Rates of restraint post (12 months) vs pre (12 months); Post period: 2,380 episodes per 3,010 admissions; Pre period: 2,379 episodes per 2,560 admissions; 13% decrease (p = NR)
Haefner, 2021, United States, Pre-post | De-esclation training (TeamSTEPPS) | Pre-intervention (practice as usual) | NR | NR
Sensory Modulation
Lloyd, 2013, Australia, Concurrent | Sensory modulation room | Concurrent control (practice as usual) | NR | NR
Cummings, 2010, United States, Concurrent | Comfort room | Concurrent control (practice as usual); Pre-intervention (practice as usual) | NR | NR
Azuela, 2018, New Zealand, Pre-post | Sensory modulation room | Pre-intervention (practice as usual) | NR | NR
Novak, 2012, Australia, Pre-post | Sensory room | Pre-intervention (practice as usual) | NR | NR
Sivak, 2012, United States, Pre-post | Comfort room; NR | Pre-intervention (practice as usual); NR | Mean Restraint Episodes Post (4 months) vs Pre (4 months); Post intervention per 1000 days of client care (Dec 2010 to Mar 2011): 0; Pre intervention per 1000 days of client care (July through Oct 2010): 0.37 per 1000 days of client care in July and 0 events in Aug, Sep, and Oct.; p = NR | NR
Smith, 2013, United Kingdom, Pre-post | Sensory room | Pre-intervention (practice as usual) | NR | NR
Zimmermann, 2020, United States, Pre-post | Serenity room | Pre-intervention (practice as usual) | NR | NR
Risk Assessment
Abderhalden, 2008, Switzerland, RCT | Structured risk assessment (BVC) | Control (practice as usual) | NR | NR
van de Sande, 2011, Netherlands RCT | Structured risk assessment (BVC) | Control (practice as usual) | NR | NR
Blair, 2017, United States, Pre-post | Structured risk assessment (BVC); 8,029 admissions | Pre-intervention (practice as usual); 3,884 admissions | Restraint events post (12 months) vs pre (12 months); Proportion of patients secluded 12 months after intervention: 5.1% (412/8029 admission); Proportion of patients secluded 12 months before intervention: 5.4% (213/3884 admission); Difference (12 months post intervention): −6%; (p = 0.44) | Duration of restraint per admission post (12 months) vs pre (12 months); Duration of restraint per admission in 12 months before intervention: NR; Difference (12 months post intervention): −52% (p = NR); Minutes in restraint post (12 months) vs pre (12 months); Mean (SD) 12 months after intervention: 445.0 (NR); Mean (SD) 12 months before intervention: 286.7 (NR); Difference p <0.01
Clarke, 2010, Canada, Pre-post | Structured risk assessment (BVC) | Pre-intervention (practice as usual) | NR | NR
Harrington, 2019, Australia, Pre-post | Risk assessment (Clinical Risk Management Initiative) | Pre-intervention (practice as usual) | NR | NR
Manning, 2022, United States, Pre-post | Risk assessment (modified Agitation Severity Scale); 389 patients | Pre-intervention (practice as usual); 353 patients | Restraint episodes; 18 months before intervention: 68 incidents; 18 months after intervention: 38 incidents; Difference: −44% (p = NS) | Minutes in restraint per episode; Mean (SD) minutes 18 months before intervention: 18 (22); Mean (SD) minutes 18 months after intervention: 10 (22); Difference: −44.4% (p = 0.047)
Trauer, 2010, Australia, Pre-post | The Management of Acute Arousal Program | Pre-intervention (practice as usual) | NR | NR
Comprehensive/Mixed
Bowers, 2015, United Kingdom, RCT | Safewards | Control wards (physical health program) | NR | NR
Välimäki, 2022, Finland, RCT | Intervention wards; 8 wards, 13 units, 335 nurses, 238 hospital beds, 4,163 patients | Control wards (practice as usual); 7 wards, 15 units, 313 nurses, 235 hospital beds, 4,186 patients | No. limb restraint events/total patients Intervention vs control; Follow-up n (proportion) intervention: 353/4089 (8.6); Follow-up n (proportion) control: 300/4092 (7.3); Baseline n (proportion) intervention: 360/4163 (8.6); Baseline n (proportion) control: 226/4186 (5.4); RR (95% CI) baseline 1.51 (0.45 to 5.14); RR (95% CI) after intervention 1.39 (0.49 to 3.98; p = 0.53); P-value for group*time: <0.001; No. patients on whom limb restraints used/total patients; Baseline n (proportion) intervention: 172/4163 (4.1); Baseline n (proportion) control: 126/4186 (3.0); RR (95% CI) 1.59 (0.57 to 4.41; p = 0.36); P-value for group time: 0.06; No. patient physical restraint events/total patients; Baseline n (proportion) intervention: 38/4163 (0.9); Baseline n (proportion) control: 27/4186 (0.7); RR (95% CI) 5.04 (0.94 to 26.96; p = 0.06); p-value for group * time: 0.05; No. of patients physically restrained/total patients; Baseline n (proportion) intervention: 23/4163 (0.6); Baseline n (proportion) control: 11/4186 (0.3); RR (95% CI) 4.74 (1.14 to 19.78; p = 0.03); p-value for group * time: 0.25 | Length per limb restraint event, geometric mean, min; Baseline geometric mean min. Intervention: 1345; Baseline geometric mean min control: 851; Log-transformed mean difference (95% CI) 0.42 (−0.62 to 1.46; p = 0.42); P-value for group * time: 0.26; Length per physical restraint event, geometric mean, min; Baseline geometric mean Intervention: 28; Baseline geometric mean control: 25; Log-transformed mean difference (95% CI) −1.33 (−3.52 to 0.86; p = 0.21); p-value for group * time: 0.16
Boumans, 2014, Netherlands, Concurrent | Methodological work approach | Control (practice as usual) | NR | NR
Noorthoorn, 2014, Netherlands, Concurrent control | Intervention | Control (practice as usual) | NR | NR
Blair, 2015, United States, Pre-post | Engagement model | Pre-intervention (practice as usual) | Annual No. restraint events post (2002–2013) vs pre (2000); Post no mechanical (manual where reported) events (2001–2013):; 2013: 0 (40); 2012: 0 (13); 2011: 0; 2010: 1; 2009: 4; 2008: 0; 2007: 0; 2006: 0; 2005: 0; 2004: 0; 2003: 0; 2002: 5; 2001: 7; Pre no events (2000): 28; Difference: NR | NR
Dickens, 2020, Australia, Pre-post | Safewards | Pre-intervention (practice as usual) | NR | NR
Hellerstein, 2007, United States, Pre-post | Comprehensive intervention; NR | Pre-intervention (practice as usual); NR | No. patients restrained month post (67 months) vs pre (20 months); Post period mean (SD): 0.32 (0.5); Pre period mean (SD): 0.35 (0.6); Difference: p = NS | Total hours patients restrained month; Pre period mean (SD): 1.7 (5.2); Post period mean (SD): 1.0 (1.1); P-value for difference: NS; % of total patients hours in restraint; Pre period mean (SD): 0.005 (0.014); Post period mean (SD): 0.003 (0.007); Difference: p = NS
Khadivi, 2004, United States, Pre-post | Comprehensive intervention; NR | Pre-intervention (practice as usual); NR | NR | NR
Lewis, 2009, United States, Pre-post | Crisis Prevention Management program; NR | Pre-intervention (practice as usual); NR | Episodes of restraint; “Each unit experienced a decrease in the use of restraint ranging from 20–97%.” | NR
McDonagh (report), 2019, United States, Pre-post | Recovery Programming; NR | Pre-intervention (practice as usual); NR | No. episode of restraint; Post period (3 years): 11; Pre period (3 years): 10; 10% increase (p = NR) | Total hours in restraint; Post period: 102.5; Pre period: 111.3; 8% decrease over time; Decreasing trend line (p = NR)
Pollard, 2017, United States, Pre-post | Comprehensive intervention | Pre-intervention (practice as usual) | NR | NR
Richmond, 1996, United States, Pre-post | Comprehensive intervention; NR | Pre-intervention (practice as usual); NR | NR | Hours in restraint post (12 months) vs pre (12 months); Post period: 1812.31 total restraint hours; Pre period: 3387.87 total restraint hours; 47% decrease in restraint hours
Stoll, 2022, Switzerland, Pre-post | Moral Case Deliberation; NR | Pre-intervention (practice as usual); NR | Proportion of patients restrained; Post period: 1.8% (n = NR); Pre period: 3.2% (n = NR); Difference: p = NS; Frequency restraint episodes among those in restraint; Post period mean (SD): 1.5 (0.6); Pre period mean (SD): 1.7 (0.08); Difference: p = 0.91 | Hours in restraint among patients restrained; Post period mean (SD): 14.5 (12.1); Pre period mean (SD): 86.8 (45.3); Difference: p = 0.02; Hours restraint per episode; Post period mean (SD): 10.1 (9.9); Pre period mean (SD): 55.2 (24.7); Difference: p = 0.01
Taxis, 2002, United States, Pre-post | Comprehensive intervention | Pre-intervention (practice as usual) | NR | NR
Whitecross, 2020, Australia, Pre-post | Psychiatric behavior of concern team | Pre-intervention (practice as usual) | NR | NR
Zuehlke, 2016, United States, High | NR | NR | NR | NR

Abbreviations. No.=number; NR=not reported; NS=not significant; OR=odds ratio; RoB=risk of bias; SE=standard error; SD=standard deviation; VA=Veteran Affairs.

## Results Summary: Composite Measures

Author, Year, Country, Design | Intervention Label, Sample Size | Comparator Label, Sample Size | Episodes of Composite Measure | Time in Composite Measure
Hospital/Unit Restructuring
Hochstrasser, 2018, Switzerland, Pre-post | Open-door policy with recovery-oriented care | Pre-intervention (practice as usual) | NR | NR
Hunter, 1993, United States, Pre-post | After hospital restructuring | Before hospital restructuring | NR | NR
Jenkins, 2014, United Kingdom, Pre-post | Purpose built psychiatric intensive care unit | Old unit | NR | NR
Rohe, 2017, Germany, Pre-post | Architecturally positive redesign | Pre-intervention (practice as usual) | NR | NR
Staff Education/Training
Bowers, 2008, United Kingdom, Concurrent and pre-post | City Nurse intervention - escalation training; 3 wards (pre-post analysis); 2 wards (concurrent analysis)^37^ | Pre-intervention (practice as usual) and concurrent control (practice as usual); 5 wards | Total Containment^38^ (pre-post analysis only); Post period mean (SD): 3.740 (2.337); Pre period mean (SD): 4.560 (2.264); Difference (among intervention wards only): p < 0.001; Concurrent control analysis:; Intervention compared to concurrent control: “no significant change” | NR
Forster, 1999, United States, Pre-post | Staff training; 3,010 admissions | Pre-intervention (practice as usual); 2,560 admissions | NR | Duration of seclusion or restraint per episode; Post period (1996): 6.3 hours/episode; Pre period (1995): 13.9 hours/episode; 54.6% decrease (p = NR)
Haefner, 2021, United States, Pre-post | De-escalation training(TeamSTEPPS) | Pre-intervention (practice as usual) | NR | NR
Sensory Modulation
Lloyd, 2013, Australia, Concurrent | Sensory modulation room; NR | Concurrent control (practice as usual); N NR | NR | NR
Cummings, 2010, United States, Concurrent | Comfort room; NR | Concurrent control (practice as usual); NR; Pre-intervention (practice as usual) | Seclusion and restraint episodes during 9-month period; “The ANOVA showed no significant changes in seclusion and restraint use with the addition of a comfort room.” | NR
Azuela, 2018, New Zealand, Pre-post | Sensory modulation room | Pre-intervention (practice as usual) | | NR
Novak, 2012, Australia, Pre-post | Sensory room | Pre-intervention (practice as usual) | NR | NR
Sivak, 2012, United States, Pre-post, High | Comfort room | Pre-intervention (practice as usual) | NR | NR
Smith, 2013, United Kingdom, Pre-post | Sensory room | Pre-intervention (practice as usual) | NR | NR
Zimmermann, 2020, United States, Pre-post | Serenity room; 172 patients | Pre-intervention (practice as usual); 149 patients | Percent of days sedation, seclusion, or restraint; Post period (61 days) 1/61 days (1.6%); Pre period (60 days): 8/60 days (13.3%); Difference: p = 0.014 | NR
Risk Assessment
Abderhalden, 2008, Switzerland, RCT | Structured risk assessment (BVC); 4 wards | Control (practice as usual); 5 wards | Composite of psychotropic medication, seclusion, and restraint; Rates of change intervention (3-months) vs control (3-months): −27% vs 10% (p < 0.001) | NR
van de Sande, 2011, Netherlands, RCT | Structured risk assessment (BVC) | Control (practice as usual) | NR | NR
Blair, 2017, United States, Pre-post | Structured risk assessment (BVC) | Pre-intervention (practice as usual) | NR | NR
Clarke, 2010, Canada, Pre-post | Structured risk assessment (BVC) | Pre-intervention (practice as usual) | NR | NR
Harrington, 2019, Australia, Pre-post | Risk assessment (Clinical Risk Management Initiative) | Pre-intervention (practice as usual) | NR | NR
Manning, 2022, United States, Pre-post | Risk assessment (modified Agitation Severity Scale) | Pre-intervention (practice as usual) | NR | NR
Trauer, 2010, Australia, Pre-post | The Management of Acute Arousal Program | Pre-intervention (practice as usual) | NR | NR
Comprehensive/Mixed
Bowers, 2015, United Kingdom, RCT | Safewards; 16 wards | Control wards (physical health program); 15 wards | Composite of 8 forms of containment^39^ as reported on the patient-staff conflict checklist intervention vs control; Baseline mean (SD) overall event rate intervention: 1.26 (1.93); Baseline mean (SD) overall event rate control: 1.39 (1.94); Ward count rate ratio (95% CI): 0.77 (0.66, 0.90; p = 0.004); Shifts with no containment event rate ratio (95% CI): 1.04 (0.83, 1.34; p = 0.71); Among wards experiencing containment events: 26.4% (9.9–34.3) reduction in events | NR
Välimäki, 2022, Finland, RCT | Intervention wards | Control wards (practice as usual) | NR | NR
Boumans, 2014, Netherlands, Concurrent | Methodological work approach | Control (practice as usual) | NR | NR
Noorthoorn, 2014, Netherlands, Concurrent | Intervention | Control (practice as usual) | NR | NR
Blair, 2015, United States, Pre-post | Engagement model | Pre-intervention (practice as usual) | NR | NR
Dickens, 2020, Australia, Pre-post | Safewards; 8 wards 142 beds | Pre-intervention (practice as usual); 8 wards 142 beds | Containment (seclusion and restraint); 4-week post intervention adjusted rate ratio (95% CI): 0.88 (0.82 to 0.94); Baseline phase (4-week prior to intervention) mean (SD) rates of containment: 6.8 (5.8); Highly coercive containment (seclusion, restraint and forced medication); 4-week post intervention adjusted rate ratio (95% CI): 0.26 (0.14 to 0.47); Baseline phase (4-week prior to intervention) mean (SD) rates of containment: 6.8 (5.8); Containment-free days; Pre vs Post period: 14.5% vs 4.9% | NR
Hellerstein, 2007, United States, High | Comprehensive intervention | Pre-intervention (practice as usual) | NR | NR
Khadivi, 2004, United States, Pre-post | Comprehensive intervention; 1,602 admissions | Pre-intervention (practice as usual); 1,766 admissions | Composite of seclusion and restraint post (12 months) vs pre (12 months); 12 months post intervention number of episodes: 148; 12 months pre intervention number of episodes: 310; % change in events in 12 months after intervention vs months before: −52% (p < 0.001) | NR
Lewis, 2009, United States, Pre-post | Crisis Prevention Management program | Pre-intervention (practice as usual) | NR | NR
McDonagh (report), 2019, United States, Pre-post | Recovery-oriented programming; NR | Pre-intervention (practice as usual); NR | Episodes of seclusion and restraint; Episodes in post period (3 years): 42; Episodes in pre period (3 years): 81; 48% decrease | Total hours in seclusion and restraint; Total hours in post period (3 years): 245; Total hours in pre period (3 years): 1,711; 86% decrease
Pollard, 2017, United States, Pre-post | Comprehensive intervention; NR | Pre-intervention (practice as usual); NR | NR | Monthly seclusion and restraint hours post (18 months) vs pre (28 months); Post period mean (SD): 55.64 (44.57); Pre period mean (SD): 182.48 (114.22); Difference: p <0.001; Hours of seclusion and restraint per patient post (18 months) vs pre (28 months); Post period mean (SD): 2.72 (2.18); Pre period mean (SD): 8.58 (6.07) Difference: p <0.001
Richmond, 1996, United States, Pre-post | Comprehensive intervention; NR | Pre-intervention (practice as usual); NR | NR | Total hours in seclusion and restraint post (12 months) vs pre (12 months); Post period: 2600.51 total combined hours; Pre period: 3783.42 total combined hours; 31% decrease in combined hours
Stoll, 2022, Switzerland, Pre-post | Moral Case Deliberation; NR; 405 total both periods | Pre-intervention (practice as usual); NR | Proportion of patients subject to formal coercion (seclusion, restraint, and forced medication); Pre period: 17.2% (N = NR); Post period: 9.6% (N = NR); Difference: p = 0.024 | NR
Taxis, 2002, United States, Pre-post | Comprehensive intervention; NR | Pre-intervention (practice as usual); NR | Incidence of seclusion and restraint; Baseline: NR; “overall reduction in the incidence of restraint and seclusion was 94%”; p = NR | NR
Whitecross, 2020, Australia, Pre-post | Psychiatric behavior of concern team | Pre-intervention (practice as usual) | NR | NR
Zuehlke, 2016, United States, High | Recovery-oriented model of care; NR; 352 total both periods | Pre-intervention (practice as usual); NR | Incidence of seclusion and restraint per month post (12 months) vs pre (12 months); Post period mean (SD) rate: 1.50 (1.17); Pre period mean (SD) rate: 3.17 (2.37); Difference; p = 0.03 | NR

## Results Summary: Patient Outcomes

Author, Year, Country, Design | Intervention Label, Sample Size | Comparator Label, Sample Size | Patient Injuries | Aggressive Incidents | Patient Satisfaction | Forced Medication
Hospital/Unit Restructuring
Hochstrasser, 2018, Switzerland, Pre-post | Open-door policy with recovery-oriented care; 14,435 patients (may include some admissions before policy which was implemented in Aug 2011); 2,803 patients in 2015 | Pre-intervention (practice as usual); 2,924 patients in 2010 | NR | NR | NR | Forced medication; aOR (95% CI) open door policy: 0.90 (0.83 to 0.98); Cases with at least 1 forced medication; Last year of post intervention follow up (2015): 1.2% (35/2803); Baseline year (2010): 2.4% (70/2924); p <0.001; Mean (SD) number of forced medication; Last year of post intervention follow up (2015): 1.2 (0.5); Baseline year (2010): 2.3 (3.2); p = 0.003
Hunter, 1993, United States, Pre-post | After hospital restructuring; 78 patients | Before hospital restructuring; 66 patients | Number of patient-patient assaults; Post N events: 6; Pre N events: 6; Number of patient-staff assaults; Post N events: 1; Pre N events: 1; Death; Post N events: 0; Pre N events: 1; Suicide attempt; Post N events: 0; Pre N events: 1; p = NR for all; only report; “There were no differences in the number of patient-to-patient assaults or patient assaults on staff” | NR | NR | NR
Jenkins, 2014, United Kingdom, Pre-post, | Purpose built psychiatric intensive care unit; 18 patients | Old unit; 18 patients | NR | No. aggressive incidents post (3–6 months) vs pre (3–6 months); Post period no. events: 16; Pre period no. events: 36; Difference: p = 0.001; No. aggressive patients post (3–6 months) vs pre (3–6 months); Post period no. events: 12; Pre period no. events: 16; Difference: NR | NR | NR
Rohe, 2017, Germany, Pre-post | Architecturally positive redesign; NR | Pre-intervention (practice as usual); NR | NR | NR | NR | Forced medication; Post period mean (SE): 0.006 (0.001); Pre period mean (SE): 0.04 (0.004); 84.4% decrease (p <0.001)
Staff Education/Training
Bowers, 2008, United Kingdom, Concurrent and pre-post | City Nurse Intervention - Escalation Training; 3 wards (pre-post analysis); 2 wards (concurrent analysis)^40^ | Pre-intervention (practice as usual) and concurrent control (practice as usual); 5 wards | NR | Conflict total per shift (pre-post analysis only); Post period mean (SD): 3.828 (3.636); Pre period mean (SD): 4.799 (3.933); Difference: p < 0.001; Verbal aggression (pre-post analysis only); Post period mean (SD):0.443 (0.766); Pre period mean (SD): 0.561 (0.912); Difference: p = 0.001; Physical aggression against objects; Post period mean (SD):0.089 (0.323); Pre period mean (SD): 0.135 (0.405); Difference: p = 0.002; Aggression against others; Post period mean (SD): 0.061 (0.288); Pre period mean (SD): 0.104 (0.366); Difference: p = 0.001; Aggression against self; Post period mean (SD): 0.084 (0.414); Pre period mean (SD): 0.075 (0.313); Difference: p = 0.232; Concurrent control analysis (for all conflict items): “On the primary outcome measures of total conflict and total containment, no significant change occurred on the experimental or control wards. The majority of conflict and containment items were also unchanged” | NR | Given PRN medication (pre-post analysis only); Post period mean (SD): 0.76 (0.95); Pre period mean (SD): 0.97 (1.15); Difference: p = 0.001; Concurrent control analysis: significantly fewer PRN (p <0.001); Given intramuscular medication (enforced); Post period mean (SD): 0.04 (0.22); Pre period mean (SD): 0.07 (0.27); Difference: p = 0.003
Forster, 1999, United States, Pre-post | NR | NR | NR | NR | NR | NR
Haefner, 2021, United States, Pre-post | De-esclation training (TeamSTEPPS) | Pre-intervention (practice as usual) | | Aggressive incidents obtained via chart review; Post period events (39 charts reviewed): 11.4%; Pre period events (67 charts reviewed): 17.3%; Difference: p = 0.024
Sensory Modulation
Lloyd, 2013, Australia, Concurrent | Sensory modulation room; NR | Concurrent control (practice as usual); NR | NR | NR | NR | NR
Cummings, 2010, United States, Concurrent | Comfort room; NR | Usual care without comfort room; NR | NR | NR | NR | NR
Azuela, 2018, New Zealand, Pre-post | Sensory modulation room; NR | Pre-intervention (practice as usual); NR | NR | | The Essen Climate Evaluation Schema (EssenCES) was used to determine staff’s and service users’ perceptions of their inpatient unit’s climate.; Unit A; [underlined: Patient’s Cohesion:]; Post: mean (SD) 3.21(.75); Pre: mean (SD) 3.00(.78); p = 0.17; Unit B; [underlined: Patient’s Cohesion]:; Post: mean (SD) 3.20(.75); Pre: mean (SD) 3.07(0.64); p = 0.33
Novak, 2012, Australia, Pre-post | Sensory room; 75^41^ | Pre-intervention (practice as usual); 75 | NR | Aggressive episodes post (12 months) and pre (12 months); Post period mean (SD): 13.9 (7.8); Pre period mean (SD): 19.6 (13.1); Difference: p = NS | NR | NR
Sivak, 2012, United States, Pre-post | Comfort room; NR | Pre-intervention (practice as usual); NR | Self-injurious behavior post (4 months) vs pre (4 months); Post intervention: 12.1% increase; Pre intervention 4-month average rate 2.32 /1,000 days of client care | Client to client assaults post (4 months) vs pre (4 months); Post intervention: 23.4% decrease; Pre intervention 4-month average rate 3.98 /1,000 days of client care | NR | NR
Smith, 2013, United Kingdom, Pre-post | Sensory room | Pre-intervention (practice as usual) | NR | NR | NR | NR
Zimmermann, 2020, United States, Pre-post | Serenity room; 172 patients | Pre-intervention (practice as usual); 149 patients | NR | NR | NR | No. benzodiazepines per day; Post period median (IQR): 1 (0 to 2); Pre period median (IQR): 2.5 (1 to 4); Difference: p < 0.001; Total amount of benzodiazepines per day.; Post period median (IQR): 1mg (0 to 3); Pre period median (IQR): 4mg (2 to 6); P-value for Difference: p 0.001; No. patients medicated per day; Post period median (IQR): 1 (0 to 1); Pre period median (IQR): 2 (1 to 3); Difference: p <0.001; Benzodiazepines dose per day when distributed.; Post period median (IQR): 2 (1.5 to 3); Pre period median (IQR): 2 (1.5 to 2); Difference: p = 0.393
Risk Assessment
Abderhalden, 2008, Switzerland, RCT | Structured risk assessment (BVC); 4 wards | Control (practice as usual); 5 wards | NR | Severe (SOARS-R score ≥9) aggressive events; Intervention group change over 3-months RR (95% CI): 0.59 (0.41 to 0.83); Control group change over 3-months RR (95% CI): 0.85 (0.64 to 1.13); Difference: p < 0.001; Physical attacks; Rates of change in intervention (3-months) vs control (3-months)l: −41% vs −7% (p < 0.001) | NR | NR
van de Sande, 2011, Netherlands, RCT | Structured risk assessment (BVC); 20 beds and 207 patients during intervention period | Control (practice as usual); 16 beds in control wards and 251 patients during intervention period | NR | Aggression incidents; 10 week baseline RR (95% CI): 1.12 (0.72 to 1.76); 30 week intervention RR (95% CI): 0.36 (0.26 to 0.50); % change in risk ratio in baseline to intervention period: −68% (p < 0.05); Aggressive patients, n; 10 week baseline RR (95% CI): 1.13 (0.57 to 3.10); 30 week intervention RR (95% CI): 0.62 (0.40 to 0.99); % change in risk ratio of no. of aggressive patients to risk ratio in intervention period: −50% (p < 0.10) | NR | NR
Blair, 2017, United States, Pre-post | Structured risk assessment (BVC) | Pre-intervention (practice as usual) | NR | NR | NR | NR
Clarke, 2010, Canada, Pre-post | Structured risk assessment (BVC) | Pre-intervention (practice as usual) | NR | NR | NR | NR
Harrington, 2019, Australia, Pre-post | Risk assessment (Clinical Risk Management Initiative); 965 admissions post-implementation | Pre-intervention (practice as usual); 1090 admissions in pre period | Self-harm/suicide attempt per 1,000 occupied bed days post (18 months) vs pre (24 months); Pre intervention rate (95% CI): 0.81 (0.44 to 1.36); Difference in rates (95% CI): −0.25 (−0.84 to 0.34); RR (95% CI): 0.69 (0.26 to 1.69; p = 0.42) | Aggression per 1,000 occupied bed days post (18 months) vs pre (24 months); Pre intervention rate (95% CI): 2.54 (1.85 to 3.41); Difference in rates (95% CI): −0.55 (−1.64 to 0.53); RR (95% CI): 0.78 (0.47 to 1.27; p = 0.33)
Manning, 2022, United States, Pre-post | Risk assessment (modified Agitation Severity Scale); 389 patients | Pre-intervention (practice as usual); 353 patients | NR | NR | Patient safety survey post (18 months) vs pre (18 months); Mean (SD) overall baseline score: 12.2 (6.38); Mean (SD) overall post score: 13.3 (8.43); Difference: p = NR | NR
Trauer, 2010, Australia, Pre-post | The Management of Acute Arousal Program | Pre-intervention (practice as usual) | NR | NR | NR | NR
Comprehensive/Mixed
Bowers, 2015, United Kingdom, RCT | Safewards; 16 wards | Staff Attention Control; 15 wards | Self-Harm Antipathy Scale; Intervention vs Control β (95% CI) 0.23 (−3.38 to 3.83; p = 0.90); Baseline mean (SD) overall event rate intervention: 78.79 (18.85); Baseline mean (SD) overall event rate control: 80/16 (21.1) | Conflict composite of 22 events reported on the patient-staff conflict checklist intervention vs control; Ward count rate ratio (95% CI): 0.85 (0.76, 0.94; p = 0.001); Ward hurdle rate ratio^a^ (95% CI): 1.14 (0.92, 1.43; p = 0.23); Baseline mean (SD) overall event rate control: 4.69 (4.60); Baseline mean (SD) overall event rate intervention: 5.22 (6.32) | NR | NR
Välimäki, 2022, Finland, RCT | Intervention wards; 8 wards, 13 units, 335 nurses, 238 hospital beds, 4,163 patients | Control wards (practice as usual); 7 wards, 15 units, 313 nurses, 235 hospital beds, 4,186 patients | Deaths Intervention vs Control; Baseline events control: 1; Baseline events intervention: 5; OR (95% CI) 4.59 (0.37 to 56.69;p = 0.23); p-value for group*time: 0.34 | NR | T reatment satisfaction Client Satisfaction Questionnaire (CSQ-8); No difference | No. of forced medication events/total patients intervention vs control; Follow-up n (proportion) intervention: 486/4089 (11.9%); Follow-up n (proportion) control: 481/4,092 (11.8%); Baseline n (proportion) intervention: 317/4163 (7.6); Baseline n (proportion) control: 414/4186 (9.9); RR (95% CI) 0.87 (0.41 to 1.83; p = 0.71); p-value for group * time: 0.56; No. of patients injected/ total patients; Follow-up n (proportion) intervention: 292/4,089 (7.1); Follow-up n (proportion) control: 289/4,092 (7.1); Baseline n (proportion) intervention: 150/4163 (3.6); Baseline n (proportion) control: 295/4186 (7.1); RR (95% CI) 1.12 (0.53 to 2.36; p = 0.76); p-value for group * time: <0.001
Boumans, 2014, Netherlands, Concurrent | Methodological work approach | Control (practice as usual) | NR | NR | NR | NR
Noorthoorn, 2014, Netherlands, Concurrent control | Intervention | Control (practice as usual) | NR | NR | NR | NR
Blair, 2015, United States, Pre-post | Engagement model | Pre-intervention (practice as usual) | NR | NR | NR | NR
Dickens, 2020, Australia, Pre-post | Safewards; 8 wards 142 beds | Pre-intervention (practice as usual); 8 wards 142 beds | NR | Conflict; 4-week post intervention adjusted rate ratio (95% CI): 0.77 (0.66 to 0.89); Baseline phase (4-week prior to intervention) mean (SD) rates: 4.0 (6.2); Physical aggression; 4-week post intervention adjusted rate ratio (95% CI): 0.65 (0.59 to 0.72); Baseline phase (4-week prior to intervention) mean (SD): 4.0 (6.2) | NR | NR
Hellerstein, 2007, United States, Pre-post | Staff education, limits on seclusion time per order, coping questionnaire, off-unit privileges; NR | Pre-intervention (practice as usual); NR | NR | No. patients involved in fights post (67 months) vs pre (20 months); Post period mean (SD): 0.3 (0.2); Pre period mean (SD): 0.5 (0.2); Difference: p = NS | NR | NR
Khadivi, 2004, United States, Pre-post | Risk assessment; 1602 admissions | Pre-intervention (practice as usual); 1766 admissions | Self-destructive behavior post (12 months) vs pre (12 months); 12 months pre intervention number of episodes: 27; 12 months pre intervention number of episodes: 24; % change in events in 12 months after intervention vs 12 months before: −11% (NS) | Assaults on patients post (12 months) vs pre (12 months); 12 months pre intervention number of episodes: 67; 12 months pre intervention number of episodes: 85; % change in events in 12 months after intervention vs 12 months before: increase 26.8% (p <0.05) | NR | NR
Lewis, 2009, United States, Pre-post | Crisis Prevention Management program | Pre-intervention (practice as usual) | NR | NR | NR | NR
McDonagh (report), 2019, United States, Pre-post | Recovery Programming; NR | Pre-intervention (practice as usual); NR | Patient assault no injury; Pre period (3 years): 1; Post period (3 years): 0; Difference NR; Patient injury; Pre period (3 years): 3; Post period (3 years): 0; Difference NR | NR | NR | NR
Pollard, 2017, United States, Pre-post | Comprehensive intervention; NR | Pre-intervention (practice as usual); NR | NR | Self-destructive events per 24-hour period pre vs post policy intervention:; Pre mean (SD): 1.07 (0.41); Post mean (SD): 0.72 (0.32); Difference: p = 0.004 | NR | NR
Richmond, 1996, United States, Pre-post | NR | NR | NR | NR | NR | NR
Stoll, 2022, Switzerland, Pre-post | Moral Case Deliberation; NR | Pre-intervention (practice as usual); NR | NR | NR | NR | Proportion of patients coerced medication; Pre period: 4.8% (n = NR); Post period: 4.1% (n = NR); Differnece: p = 0.93
Taxis, 2002, United States, Pre-post | Comprehensive intervention | Pre-intervention (practice as usual) | NR | NR | NR | NR
Whitecross, 2020, Australia, Pre-post | Multidisciplinary team approach; 1356 episodes of care total | Pre-intervention (practice as usual) | Self-harm post (6 months) vs pre (6 months); No. 6 months before intervention: 20; Difference (6 months post): −25% (p = NR) | Physical aggression post (6 months) vs pre (6 months); No. 6 months before intervention: 163; Difference (6 months post): −25.2% (p = NR); Verbal aggression post (6 months) vs pre (6 months); No. 6 months before intervention: 188; Difference (6 months post): −23.4% (p = NR) | NR | NR
Zuehlke, 2016, United States, Pre-post | Recovery-oriented model of care | Pre-intervention (practice as usual) | NR | NR | NR | NR

Notes.

a Test for difference (intervention vs control) in number of shifts with 0 events.

Abbreviations. aOR=adjusted odds ratio; no.=number; NA=not applicable; NR=not reported; NS=not significant; OR=odds ratio; RoB=risk of bias; SE=standard error; SD=standard deviation; VA=Veteran Affairs.

## Results Summary: Staff Outcomes

Author, Year, Country, Design | Intervention Label, Sample Size | Comparator Label, Sample Size | Staff Injuries | Satisfaction with Policy
Hospital/Unit Restructuring
Hochstrasser, 2018, Switzerland, Pre-post | Open-door policy with recovery-oriented care | Pre-intervention (practice as usual) | NR | NR
Hunter, 1993, United States, Pre-post | After hospital restructuring; 78 patients | Before hospital restructuring; 66 patients | Patient-to-staff assaults; Pre no. events: 1; Post no. events: 1 | NR
Jenkins, 2014, United Kingdom, Pre-post | Purpose built psychiatric intensive care unit | Old unit | NR | NR
Rohe, 2017, Germany, Pre-post | Architecturally positive redesign | Pre-intervention (practice as usual) | NR | NR
Staff Education/Training
Bowers, 2008, United Kingdom, Concurrent and pre-post | City Nurses intervention – escalation training | Concurrent control (practice as usual) | NR | NR
Forster, 1999, United States, Pre-post | Intensive staff training; 3,010 admissions | Pre-intervention (practice as usual); 2,560 admissions | Staff injuries post (12 months) vs pre (12 months); Post period: 39 incidents; Pre period: 48 incidents; 18.8% decrease (p = NR) | NR
Haefner, 2021, United States, Pre-post | De-esclation training (TeamSTEPPS) | Pre-intervention (practice as usual) | NR | NR
Sensory Modulation
Lloyd, 2013, Australia, Concurrent | Sensory modulation room; N NR | Concurrent control (practice as usual); N NR | NR | NR
Cummings, 2010, United States, Concurrent | Comfort room | Concurrent control (practice as usual); Pre-intervention (practice as usual) | NR | NR
Azuela, 2018, New Zealand, Pre-post | Sensory modulation room; N NR | Pre-intervention (practice as usual); N NR | NR | The Essen Climate Evaluation Schema (EssenCES) was used to determine staff’s and service users’ perceptions of their inpatient unit’s climate.; Unit A; [underlined: Experienced Safety:]; Post: mean (SD) 2.94(0.67); Pre: mean (SD) 3.40 (0.84); P = 0.11; [underlined: Therapeutic Hold:]; Post: mean (SD) 3.29 (0.65); Pre: M (SD) 3.33 (0.83); p = .59; [underlined: Overall Climate]:; Post: mean (SD) 3.18 (0.60); Pre: mean (SD) 3.31 (0.76); p = .27; [underlined: Overall Attitudes (measured] Professional Attitudes Towards Seclusion Questionnaire (PATS-Q):; Median (post): 2.87 (0.36); Median (pre): 2.89 (0.61); p = .47; Unit B; [underlined: Experienced Safety]:; Post: mean (SD) 3.31 (0.69); Pre: mean (SD) 3.33 (0.49); p = 1.00; [underlined: Therapeutic Hold]:; Post: mean (SD) 3.73 (0.73); Pre: mean (SD) 3.41 (0.61); p = .02; [underlined: Overall Climate]:; Post: mean (SD) 2.63 (0.90); Pre: mean (SD) 2.80 (0.71); p = .10; [underlined: Overall Attitudes (measured PATS-Q):]; Median (post): 2.8857 (0.56); Median (pre): 2.75 (0.39); p = 0.70
Novak, 2012, Australia, Pre-post | Sensory room | Pre-intervention (practice as usual) | NR | NR
Sivak, 2012, United States, Pre-post | Comfort room; NR | Pre-intervention (practice as usual); NR | Client to staff assaults post (4 months) vs pre (4 months); Post intervention: 48.1% decrease; Pre intervention 4-month average rate 2.31 /1,000 days of client care
Smith, 2013, United Kingdom, Pre-post | Sensory room | Pre-intervention (practice as usual) | NR | NR
Zimmermann, 2020, United States, Pre-post | Serenity room | Pre-intervention (practice as usual) | NR | NR
Risk Assessment
Abderhalden, 2008, Switzerland, RCT | Structured risk assessment (BVC) | Control (practice as usual) | NR | NR
van de Sande, 2011, Netherlands, RCT | Structured risk assessment (BVC) | Control (practice as usual) | NR | NR
Blair, 2017, United States, Pre-post | Structured risk assessment (BVC) | Pre-intervention (practice as usual) | NR | NR
Clarke, 2010, Canada, Pre-post | Structured risk assessment (BVC) | Pre-intervention (practice as usual) | NR | NR
Harrington, 2019, Australia, Pre-post | Risk assessment (Clinical Risk Management Initiative); 965 admissions post-implementation | Pre-intervention (practice as usual); 1,090 admissions in pre period | | Staff survey post (18 months) vs pre (24 months); [underlined: Visual observations contribute to safe practice at [this psychiatric unit].]; P-value for difference = 0.17; [underlined: Visual observations create a safe environment for patients.]; P-value for difference = 0.17; [underlined: I am personally satisfied with the practice of visual observations in the management of patients who have been identified as being ‘at risk’:]; Improve post intervention. P-value for difference = 0.01; [underlined: The current way in which we do visual observations prevents adverse outcomes for staff.]; P-value for difference = 0.33; [underlined: The current way in which we do visual observations prevents adverse outcomes for patients.]; P-value for difference = 0.12; [underlined: Visual observations provide optimum care for the patients at [this psychiatric unit].]; Improve post intervention. P-value for difference <0.001
Manning, 2022, United States, Pre-post | Risk assessment (modified Agitation Severity Scale); 389 patients | Pre-intervention (practice as usual); 353 patients | NR | Nurse survey post (18 months) vs pre (18 months); “No significant difference between study phases”; Oldenburg burnout scale post (18 months) vs pre (18 months); Mean (SD) baseline: 36.17 (6.74); Mean (SD) post: 36.11 (8.29); Difference in overall score: p = 0.98
Trauer, 2010, Australia, Pre-post | The Management of Acute Arousal Program | Pre-intervention (practice as usual) | NR | NR
Comprehensive/Mixed
Bowers, 2015, United Kingdom, High | Safewards; 16 wards | Control wards (physical health program); 15 wards | NR | Ward atmosphere scale intervention vs control (positive values represent improvements for intervention); [underlined: Order and organization]; β (95% CI) −0.32 (−0.79 to 0.16; p = 0.20); Baseline mean (SD) overall event rate control: 6.43 (2.53); Baseline mean (SD) overall event rate intervention: 7.19 (2.27); [underlined: Programme clarity]; β (95% CI) 0.27 (−0.22 to 0.75; p = 0.28); Baseline mean (SD) overall event rate control: 7.18 (2.06); Baseline mean (SD) overall event rate intervention: 7.4 (2.04); [underlined: Staff control]; β (95% CI) −0.19 (−0.57 to 0.18; p = 0.30); Baseline mean (SD) overall event rate control: 1.8 (1.40); Baseline mean (SD) overall event rate intervention: 1.83 (1.55)
Välimäki, 2022, Finland, RCT | Intervention wards; 8 wards, 13 units, 335 nurses, 238 hospital beds, 4,163 patients | Control wards (practice as usual); 7 wards, 15 units, 313 nurses, 235 hospital beds, 4,186 patients | NR | Nurse turnover rates; No difference; Team climate inventory; No difference
Boumans, 2014, Netherlands, Concurrent | Methodological work approach | Control (practice as usual) | NR | NR
Noorthoorn, 2014, No PMID, Netherlands, Concurrent | Intervention | Control (practice as usual) | NR | NR
Blair, 2015, United States, Pre-post | Engagement model | Pre-intervention (practice as usual) | NR | NR
Dickens, 2020, Australia, Pre-post | Safewards; 8 wards 142 beds | Pre-intervention (practice as usual); 8 wards 142 beds | NR | Violence Prevention Climate Scale (VPC-14); Staff and patient perceptions regarding violence prevention: “Did not change”
Hellerstein, 2007, United States, Pre-post | Comprehensive intervention; NR | Pre-intervention (practice as usual); NR | No. patient related staff injuries post (67 months) vs pre (20 months); Pre period mean (SD): 0.7 (1.0); Post period mean (SD): 0.18 (0.42); Difference: p = 0.003 | NR
Khadivi, 2004, United States, Pre-post | Comprehensive intervention; 1,602 admissions | Pre-intervention (practice as usual); 1,766 admissions | Assault on staff post (12 months) vs pre (12 months); 12 months pre intervention number of episodes: 31; 12 months post intervention number of episodes: 83; % change in events in 12 months after intervention vs 12 months before: 167%; (p <0.01) | NR
Lewis, 2009, United States, Pre-post | Crisis Prevention Management program | Pre-intervention (practice as usual) | NR | NR
McDonagh (report), 2019, United States, Pre-post | Recovery-oriented programming; NR | Pre-intervention (practice as usual); NR | Staff injury; Pre period (3 years): 3; Post period (3 years): 0; Difference NR; Staff assault no injury; Pre period (3 years): 0; Post period (3 years): 2; Difference NR | NR
Pollard, 2017, United States, Pre-post | Comprehensive intervention; NR | Pre-intervention (practice as usual); NR | | Critical incidents (potential or actual assaultive or self-destructive events occurring on the unit in 24-h period) post (18 months) vs pre (28 months); Pre period mean (SD): 1.07 (0.41); Post period mean (SD): 0.72 (0.32); P-value for difference = 0.004
Richmond, 1996, United States, Pre-post | Comprehensive intervention | Pre-intervention (practice as usual) | NR | NR
Stoll, 2022, Switzerland, Pre-post | Moral Case Deliberation | Pre-intervention (practice as usual) | NR | NR
Taxis, 2002, United States, Pre-post | Comprehensive intervention | Pre-intervention (practice as usual) | NR | NR
Whitecross, 2020, Australia, Pre-post | Psychiatric behavior of concern team | Pre-intervention (practice as usual) | NR | NR
Zuehlke, 2016, United States, Pre-post | Recovery-oriented model of care; 352 total both periods | Pre-intervention (practice as usual); 352 total both periods | NR | Staff satisfaction; Pre period: NR; Overall stratification higher in post vs pre period (p = 0.04); Increases in staff satisfaction for daily programming (p = 0.001), satisfaction with staff collaboration (p = 0.003), ability to handle acute situations without using restraints (p = 0.008), ability to provide group programming (p = 0.09, and belief that patients should have input into their mental health treatment (p = 0.005).

36 Independent sample size is unclear. Study reports sample to experience seclusion events, which may have included the same individual multiple times.

37 One of the 3 intervention wards (“Ward 5”) was excluded from analysis as it was at the same hospital as “Ward 3” and had a short intervention period.

38 Containment defined as a composite of means by which ward staff “keep patients safe, including extra medication given at nurses discretion, special observation, and manual restraint.”

39 Defined as actions taken by staff to manage unsafe patients such as coerced medication, seclusion, restraint, special observation, etc.

40 One of the 3 intervention wards (“Ward 5”) was excluded from analysis as it was at the same hospital as “Ward 3” and had a short intervention period.

41 Independent sample size is unclear. Study reports sample to experience seclusion events, which may have included the same individual multiple times.